# Afterword

## Afterword to the Surgeon General’s Report

I have long been passionate about finding ways to better our country through the creativity and innovation that results from the public and private sectors working together toward a common good. I am pleased that the Surgeon General is, through this report, exploring the important role that the business community plays in improving our country’s health, and demonstrating so clearly the inextricable link between community health and economic prosperity.

As I pen this, we are at an unparalleled moment in our nation’s history because of the wide-ranging impacts resulting from the arrival of COVID-19 on our shores. Of course, this Surgeon General’s Report was conceived quite some time ago, when the next pandemic was only theoretical and far from top of mind for most Americans. COVID-19 presents a formidable challenge to the world and to the United States. Because of COVID-19, we have lost loved ones and colleagues, families have endured difficult economic circumstances like job loss, our daily lives have been disrupted, and our perspectives on health and the economy have been altered.

Our national focus on responding to this public health emergency does not take away from the important messages in this report. In fact, it now seems prescient and highly relevant that the Surgeon General chose to focus on the connections between community health and economic prosperity and the role of business, particularly investing in one to achieve the other. The inextricable link between the health of businesses and the health of communities has never been more apparent. From employees and customers to suppliers and service providers, it is strikingly obvious how interconnected and interdependent we are today.

I would like to reflect on the impacts of this pandemic and some of the truths it has revealed. To address this public health emergency, federal, state, and local governments have had to make difficult decisions, including temporarily suspending activities to create the physical distancing needed to flatten the curve. The phrase flattening the curve was foreign to all but public health officials at the beginning of 2020, but that phrase is now common parlance as everyone’s cooperation is needed to address the COVID-19 pandemic.

The private sector has also made tough choices, including voluntarily adapting on short notice to working remotely, canceling long-planned conferences and business travel, suspending sports leagues, and altering operations or even closing businesses for periods of time to keep employees and customers safe. These choices have affected nearly all business settings, from office jobs and restaurants to manufacturing, packaging, and retail operations.

Through this pandemic, company leaders have stepped up to take actions in the public interest despite the effects those action have on their bottom lines. There is no doubt that these decisions are hard on businesses. From one-person start-ups to major multinational corporations, nearly all have felt the pain of the slowdown in business and the impacts on revenue. But ultimately, these dramatic actions are needed to protect the health of the American public, our businesses, our economy, and our future.

But the story does not stop at the health and economic devastation resulting from this pandemic. A broader lens reveals how we can use this experience to ultimately improve our health and our economy and prevent similar devastation from a future threat. While our battle against COVID-19 is not yet over, I am eager to begin documenting our collective observations, perspectives, and lessons learned from confronting this challenge. It may be too early at this point to draw definitive conclusions, but I am certain that we must begin this work now, before too much time passes and we have moved on to other concerns or forgotten what we saw in the first half of 2020. Next, I will share some of my reflections about the underlying problems this pandemic has spotlighted and how our systems can adapt to meet the needs of our population.

First, in addition to showing the clear link between business and health, this pandemic has revealed, sometimes in stark terms, how social and economic stressors influence health. I cofounded the National Alliance to Impact the Social Determinants of Health (NASDOH), partly out of recognition that we need to engage the business community to articulate the whole-of-society value proposition for addressing the social determinants of health—or what this report refers to as the vital conditions that shape health, wealth, and well-being. NASDOH encourages public and private sector leaders to work together to address the conditions in the environments in which people are born, live, learn, work, play, worship, and age that affect health, functioning, and quality-of-life outcomes and risks.

NATIONAL ALLIANCE TO IMPACT THE SOCIAL DETERMINANTS OF HEALTH

NASDOH is a multisector group of stakeholders that works to systematically and pragmatically build a common understanding of the importance of addressing social needs and determinants as part of an overall approach to improve health. NASDOH focuses on advancing public and private sector policy environments to support the development of the evidence base upon which work in the field can build, innovate, and be sustained.

In past emergencies like natural disasters, we have seen that some communities are particularly vulnerable to the health and economic effects stemming from such tragedies. With the spread of COVID-19, we have seen that racial and ethnic minorities, older individuals, and those with underlying health conditions—such as obesity, diabetes, and hypertension—are particularly at risk of complications and death from the virus. As a result, individuals with these conditions have had poorer outcomes than those without such underlying circumstances. The fact that these conditions are so common in America has created additional demands on the healthcare delivery system.

Now we can see that we would be better off if we had invested more to prevent the development of chronic conditions in these higher risk communities and to better manage the conditions once they are diagnosed. As this report discusses, business plays a critically important role in promoting community health—to both business and community—and we should work together to help position ourselves better before the next emergency. Many of the actions that will ease the impact of an emergency like COVID-19 can also help to address the conditions that cause premature death every day in America. This report highlights several of these actions, including (a) helping more Americans to become financially secure and gain the skills and support they need to be successful on the job and (b) increasing access to quality affordable housing and safe green spaces, quality early childcare and development programs, and reliable transportation. These efforts will remain public health urgencies long after COVID-19 is a memory.

The economic disruptions caused by COVID-19 have hit Americans hard, particularly vulnerable communities. Unemployment and food insecurity have skyrocketed, and many workers have lost their healthcare coverage. Many people who work in the service sector, the “gig work” economy, and other customer-facing jobs have not transitioned easily to working remotely, resulting in tens of millions of furloughs and job losses. Workers deemed “essential”—such as grocery store and food service employees, bus drivers, home health aides, convenience store workers, and first responders—have retained their jobs but at the cost of being far more likely to be exposed to the virus. Financial insecurity and a lack of paid sick leave meant staying home from work when ill was not a viable option for most of these lower-wage workers.

Second, when we look back at the country’s response to this pandemic, I think it is important to remember all it took to fight COVID-19. The immediate response to this crisis required testing capacity, personal protective equipment to protect our healthcare work force, medicines and equipment to treat those who were sick, and vaccine development to protect the population as a whole. But medical care for individual patients is only part of the story. We also needed public health functions, like contact tracing; social services, like food pantries for the food insecure and meal delivery for the homebound; and childcare supports and transportation options to help essential workers report to their jobs. And we had to work together to make and support decisions that benefit all of us, not just one sector, population group, or location.

Our healthcare workers on the frontlines of the pandemic face immense challenges just to keep up with the demands and changes in practices to ensure that patients and staff are safe. Our social care systems are also strained, having to adapt and create new ways of delivering services amidst the demands and challenges from the pandemic.

When we think in the future about the infrastructure and personnel that our country needs to support health, I hope we will remember the importance of

■ Hospital beds, equipment, and frontline healthcare providers;
■ Public health and social services programs, personnel, and systems;
■ Community cohesion and neighborhood resources; and
■ The vital conditions that shape health, wealth, and well-being, which are missing from too many American communities.

Moving forward, we must address all the factors that contribute to worse health and economic outcomes and higher risk for so many Americans, so that next time we can reduce (a) the economic impact and the burden of disease on those individuals and (b) the overall burden on healthcare delivery.

Finally, the COVID-19 pandemic has showed to us the broad view needed to restore health and economic prosperity across sectors and to better strengthen and prepare resilient communities, so we can sustain health and economic prosperity for all our neighbors. The actions we’ll need to take to recover and rebuild from the pandemic will challenge us all to play a part—as individuals, families and communities, as well as the public, private, and nonprofit sectors.

This report recognizes that business plays an important role in strengthening communities, creating value, and building shared prosperity. Business can also be an important partner to public health departments, social services systems and enterprises, and community development organizations that have proven so vital in this pandemic and in the decades-long efforts to build healthy and resilient communities and expand opportunities for more Americans. Let us not waste this opportunity to learn from what we have been through and to challenge businesses to engage with communities and serve as leaders in improving health for all.

As this report so eloquently demonstrates, business can and should play a role in improving community health and economic prosperity for all. Now, more than ever, we need the business community’s commitment, energy, and devotion to do so. To make the biggest impact and do the most good as we emerge from this pandemic, business leaders should listen to their communities about their unique needs. The challenges in each community varied before this crisis, and communities will emerge from it with different needs as well. I believe we serve best when we listen and learn first, and all of us, including the business community, should rise to the challenge with this spirit in mind.

I will leave you with a final thought. In time, COVID-19 will be conquered by human ingenuity. Until then, it is a problem that must be managed daily. The virus presents a new set of risks that we must learn to navigate together. Although the sense of suffering the pandemic brings is most unwelcome, it will also bring renewal. Hardships like this have a way of renewing our collaborative spirit, inspiring innovation, breaking down bureaucratic obstacles, and scrapping away hubris. We can endure this and become better people and a stronger nation.