# Perspectives From Business Leaders

## OVERVIEW

This section presents perspectives from business leaders who describe multifaceted investments in communities. They explain what was done and why it was done, the impact on community health and economic prosperity, and the value for business. Read about their principles, the importance of childcare and families for the future, and how to build lasting collaborations that strengthen health and prosperity. Perspectives from three organizations are presented: Centene Corporation; Hillenbrand, Inc.; and Shakopee Mdewakanton Sioux Community.

## Centene Corporation Perspective

### The Power of Community

At Centene Corporation (Centene), we believe that economic prosperity relies on investment. When Betty Brinn started Family Hospital Physician Associates (FHPA) in 1984, some 19 million people were eligible for Medicaid across the United States. Once a child in the foster care system and later a mother of four, Brinn was determined to make quality healthcare available to those in need. In her 8 years of pursuing that mission, Brinn grew FHPA from a pilot, nonprofit, Medicaid-managed care plan, housed in the basement of a hospital in Milwaukee, Wisconsin, to a $40-million, for-profit company with 40,000 members.

This purpose and growth attracted me to join the company as chief executive officer in 1996, renaming it Centene in 1997. I appreciated the values of Brinn’s organization and shared her belief that every person is entitled to quality healthcare delivered with dignity. From this point, I set out to bring the company’s managed care services to as many people as possible. Prior to joining Centene, I had learned to harness the power of local brands. Having spent years in the consumer products industry, I brought these lessons to Centene and believed the company could grow by tailoring healthcare to specific community needs and allowing bold, independent health plan leaders to retain authority and accountability in their local markets. This approach became the foundation of Centene’s business model and culture.

Today, Centene has become the largest Medicaid managed care organization (by membership) in the United States, a national leader in managed long-term services and supports, and the top insurer in the nation on the Health Insurance Marketplace. Annual revenues exceeded $74 billion in 2019. Centene goes beyond traditional healthcare by partnering with states and other stakeholders to offer programs and services that address the health and social needs of the country’s most vulnerable populations. Centene provides healthcare coverage to approximately 1 in 15 individuals across the nation.

Headquartered in St. Louis, Missouri, Centene employs more than 69,000 people. Centene’s presence in the St. Louis area is evident across the city’s landscape, from its global headquarters in downtown Clayton to its $35-million service center in Ferguson. The service center exemplifies Centene’s commitment to the region.

In August 2014, the world focused on the St. Louis suburb of Ferguson as protesters and police violently clashed following the shooting death of 18-year old Michael Brown, Jr., by a Ferguson police officer. The city’s businesses and residents were besieged by fires, vandalism, and riots, and the future of this small community hung in the balance. Ferguson’s problems were not unique to Missouri and could have taken place in any community in the United States.

Centene was among the first of many corporations in St. Louis to see the importance of supporting the community of Ferguson. Plans for a new facility in Ferguson moved quickly; fewer than 18 months elapsed between the site announcement and the grand opening. The new facility, named the Centene Service Center, opened in Ferguson in April 2016 and provides many amenities for employees and the community, including a community education center, internship programs, and an early childhood development center. It also brought 250 new jobs. Reaching young people in Ferguson and surrounding communities became part of Centene’s strategy to help Ferguson move forward. Centene partnered with Normandy High School to connect students in the Ferguson area with a mentor and an internship at the service center. Dr. Charles Pearson, superintendent of the Normandy Schools Collaborative, said the partnership with Centene, “is another way to help our students make the connection between what they’re learning in the classroom and how it can have a positive impact on their futures.”

Centene also partnered with the Greater St. Louis Boys and Girls Club to launch Ferguson’s first Boys and Girls Clubs in two of the city’s elementary schools, paving the way for 400 children to enroll in the club’s summer and afterschool programs. Additionally, Centene partnered with the Urban League of Metropolitan St. Louis to build a new job training center on the site of the former QuikTrip location that was destroyed during the protests.

Centene is an important partner in the St. Louis region and in Missouri. Centene’s Missouri subsidiary, Home State Health, is also headquartered in the St. Louis area and serves families enrolled in the state’s Medicaid program. Since 2012, Home State has partnered with local and statewide physicians, hospitals, and other providers to care for more than 315,000 members across Missouri.

### External Influences on Well-Being

We at Centene recognize the vital conditions that influence community health. Coincidentally, these conditions align with our company’s industry sector and underscore the scope of our impact: Centene can successfully provide for the health of its members only if we address the underlying conditions that often stand in the way of members achieving health in the first place.

Through our health plans, Centene has piloted several programs that address areas of influence over health (housing, food, education, employment and transportation), for example:

■ Transportation. Rideshare pilot programs demonstrate improvement in quality of service and reduction in cost across several populations—that is, a 16-percentage point increase in on-time arrivals to appointments (from 83% to 99%) and a 15–18% reduction in cost for non-emergency medical transportation.
■ Community navigation. Social prescribing services assess support needs and connect individuals with local resources. A partnership between a health plan and community hub provides navigators who help families access local services and provides interpersonal support. For those engaged, birth outcomes improved for high-risk members, demonstrating a 136% return on investment ($2.36 for every $1 invested).
■ Housing. Participating in a continuum of care, which uses homelessness data from the U.S. Department of Housing and Urban Development to ensure coordinated entry for members experiencing homelessness, resulted in improved health outcomes and costs, including a 9% reduction in inpatient behavioral health visits per month.

### Experimentation and Investments to Transform the Status Quo

The path to these programs requires a recognition of the importance of complex systems; the challenges are too large and complex to be solved by a single organization or industry. There is a discernable need to transform the healthcare industry from a series of single-actor silos to cross-sector partners.

Our approach contributes to operational practices and data analytic capabilities. We initially test our pilot initiatives through health plans in individual states, and when appropriate, bring our work to the national conversation. Below are a few ways in which we continue to experiment and invest in serving the health and social needs of our country’s most vulnerable populations.

■ Centene’s Social Determinants of Health Innovation team leverages our local and national relationships to advance the healthcare industry’s approach to addressing the barriers that keep members from achieving optimal health. Across multiple states, our health plans have implemented community-integrated social services technology platforms to connect members with community benefit organizations. For example, Buckeye Health Plan, Centene’s subsidiary in Ohio, participates in the Pathways Community Hub partnership to identify and address barriers to care for vulnerable persons. By connecting members to community supports and resources via the Hub, Buckeye Health Plan has significantly (a) improved birth outcomes for women who are most at risk of low birthweight deliveries and (b) reduced admissions to neonatal intensive care units.
■ Through a partnership among Centene, Washington University in St. Louis, and Duke University, the Centene Center for Health Transformation fosters research collaborations, demonstrates thought leadership, and initiates innovative new programs. For example, a study of the Centene Center for Health Transformation indicated that interventions to help identify and manage unmet social needs may improve health by lowering stress levels and increasing positive health behaviors. In addition, the Centene Center is currently working with Centene’s health plans in Louisiana, Missouri, and Florida to evaluate the impact of peer coaches on reducing childhood obesity, specifically through dietary and activity habits.
■ Centene’s Social Health Bridge™ Trust is designed to bring data-driven and evidence-based approaches to such entities as physicians, hospital systems, Accountable Care Organizations, payers, and health departments to address conditions that shape the health of individuals and communities.

### Investing in Alliances

Firms operate in social and political contexts. The importance of strong relationships with states and local communities should not be underestimated. Strengthening relationships is not easy and takes time. Even in this domain, we’ve embraced a longtime mantra of mine: “We have to be different. Be first.”

This means that, as with our business approach, we make thoughtful investments into communities that may not pay off for years. Also, because scientific research is not always available, we must experiment, test, verify, and expand, often while leading others. We do this is because the fate of our business units is inextricably tied to our communities.

[W]ith our business approach, we make thoughtful investments into communities that may not pay off for years.

In recent years, we have expanded our presence in several cities, with an eye to increasing the economic health and development of these areas, including Sacramento, California and Farmington, Missouri. We have many instrumental partners who have enabled our economic, civic, healthcare, and educational involvement at the local level—all of which contribute to an enriched environment that empowers healthier decisions to create more vibrant families and communities.

On February 21, 2019, Centene dedicated the cornerstone of a new 68-acre campus in the North Natomas region of Sacramento, California. The facility represents the biggest private sector job recruitment in the modern history of Sacramento. Construction is underway, and the campus will serve as a regional hub for Centene. Sacramento Mayor Darrell Steinberg recognized the power of Centene’s presence in California: “We are welcoming a new community leader to Sacramento. Centene and Health Net are at the forefront of serving some of the community’s most vulnerable people.” Health Net, Centene’s health plan in California, is a wholly owned subsidiary of Centene that was acquired in 2016.

“When a growing city and a great company are serious about creating jobs and real opportunity for people, we can both move mountains.”

—Darrell Steinberg

Centene’s expansion was noted as a victory for Sacramento. Mayor Steinberg praised Centene’s partnership with Sacramento on this effort: “The way this all came together says a lot about both Sacramento and Centene. When a growing city and a great company are serious about creating jobs and real opportunity for people, we can both move mountains. The Centene agreement may not be the exception; in fact, it’s the model of where the public sector and the private sector coming together is both a big winner for the city and for the company.”

### Strategic Growth and Continued Partnerships

While Centene believes that businesses have opportunities to address social and economic disparities through investments and creativity, we also recognize that state and federal governments play a role in aligning incentives and supporting provisions for these services. We support policies that enable innovation, such as (a) state Medicaid actions to include any nonemergency medical transportation benefits in their Medicaid managed care programs and (b) removing regulatory barriers to health plans developing innovative ridesharing programs.

We also support policies that increase financial support to pay for these services through public programs, such as Medicare Advantage policies that encourage health plans to innovate. For example, some health plans now offer supplemental benefits and other demonstration programs that can test the effectiveness of these investments. More can be done to allow states and localities to combine and utilize all relevant public funding streams to better target and develop a full suite of services to facilitate whole-person care.

We must develop new products and partnerships to better serve the needs of the community. Sustaining growth requires increased differentiation from competitors. Centene realizes that setting the terms of competition by being the first to enter a market or by using a particular strategy, such as having affiliated in-house companies provide a seamless whole-person approach to care, positions the company for continued success. Success also requires a measured appetite for risk, an ability to act quickly, and a foundation of patience and disciplined investment to build relationships in each new market and to design products that meet the changing needs of local communities.

With continued investments in communities and a steadfast commitment to the guiding principles of the enterprise, Centene strives to improve the health of its members; works to combat health inequities; and returns value to our shareholders, our partners, and, most importantly, the communities we serve.

## Hillenbrand, Inc. Perspective

### Hillenbrand Today

Hillenbrand, Inc. (Hillenbrand) is a global diversified industrial company headquartered in Batesville, Indiana. We employ more than 12,000 people worldwide at multiple leading brands that serve a wide variety of industries. The company is also an anchor institution in the Batesville area.

Our portfolio includes companies that design, develop, manufacture, and service highly engineered industrial equipment, and Hillenbrand’s legacy company, Batesville, is a recognized leader in the death care industry in North America.

Hillenbrand strives to provide superior return for shareholders, exceptional value for customers, and great professional opportunities for employees and to be responsible to our communities.

### Hillenbrand’s Roots

Despite operations in more than 40 countries, we remain headquartered in the heart of the United States. Batesville is a small city in Southeastern Indiana, nestled halfway between Indianapolis and Cincinnati (Ohio). The relationships between this community of 6,000 people and the company are deep and resilient.

John A. Hillenbrand planted the company’s roots in Batesville in 1906 when he rescued a small, struggling casket company. Since then, the company has recognized the importance of the relationship between an anchor institution and a community and the value that keeping innovation and continuous improvement in focus brings to both.

The company was then, and is today, a true community partner, employing hundreds of the city’s residents and helping to fuel growth in education, the arts, and the economy.

### Challenges in Small, Rural Communities

Remaining headquartered in a rural community in the United States poses several challenges that require partnerships to develop practical solutions. We have learned this about being an anchor institution and community partner: No institution can single-handedly overcome challenges or create and sustain solutions on its own.

No institution can single-handedly overcome challenges or create and sustain solutions on its own.

Consider the challenge of rural population growth: it is flat at best and in decline at worst.

While Hillenbrand continues to grow, the population of our hometown and surrounding rural communities is dwindling, posing a serious challenge for Hillenbrand and other companies seeking qualified workers. Students are leaving for college and not returning to the local workforce; the birth rate is declining as the existing population ages; and immigrants and their families are settling in larger cities. These trends leave companies like Hillenbrand facing a steady decline of available working-age employees and a gap in skills needed to perform critical jobs.

■ To help rural communities thrive, policymakers, business leaders, and educational institutions must work together to reduce the population decline, address the skills gap, and attract and retain new workers. For example, rural communities need quality healthcare with nearby access to obstetric and gynecologic (OB-GYN) services so young families can grow without having to drive 2 hours to an OB-GYN appointment; and
■ Formal programs are needed to close gaps in skills and provide talent pipelines to sustain and grow local businesses.

Each of these is a long-term investment that might not yield immediate dividends, but they are important to the vitality of the community and the company. Hillenbrand has focused on these and other efforts to foster a talent ecosystem that attracts and retains the next generation of workers and creates sustainable communities.

### The Unique Role of Anchor Institutions

Students, graduates, and young families are opting first for quality of place. They are moving, with or without a job or income, to interesting locations with the amenities they seek. Because rural communities often do not have these amenities—such as diversity, arts, and cultural experiences—rural communities develop quality of place for themselves.

To better understand and address the various challenges facing rural communities, Indiana’s Task Force on Rural Affairs built a coalition of rural business and thought leaders, including representatives of Hillenbrand, from across the state for a year. The task force discovered that quality of place for rural communities hinges on the presence of quality education and industry (business and employment), an anchor institution, and a hospital or healthcare facility with an obstetric practice. The lack of public transportation in rural communities means these essentials must exist within 30 miles of a city’s center.

With these insights, Hillenbrand joined with others to make hospital services in Batesville a priority, and to focus philanthropic, workforce, and community relations efforts on education, industry, and healthcare. These community assets will determine the vitality and sustainability of our rural communities for years to come.

### Building Regional Capacity

Building on the successes of similar programs, the Hillenbrand Community Leadership Series (HICLS) annually assembles 20 people from the company and community to engage in strategic discussions with business and civic leaders. The group is often used as a “think tank” for the community, studying and solving large issues facing the community, including diversity and inclusion, workforce skills, and the development of a vibrant downtown to build Batesville and Southeastern Indiana into attractive places to live and work. Indeed, quality of place featured prominently in a 2015 HICLS survey showing that a lack of entertainment, dining, and shopping are among the top reasons people who work in Batesville chose to live elsewhere.

Indianapolis, just 50 miles northwest of Batesville, is home to a world-renowned symphony orchestra. People looking to enjoy this level of art and culture were not finding it in or around Batesville. Hillenbrand worked with the Batesville Area Arts Council to create a 3-year strategic partnership with the Indianapolis Symphony Orchestra (ISO). The partnership coordinates the Star-Spangled Symphony. ISO transports a stage and its musicians to Batesville for a concert. The performance is accompanied by fireworks, bringing to Batesville a patriotic event that most area residents would have to travel a significant distance to see otherwise. A network of regional sponsors helps to make the event successful, including financial and volunteer support from Hillenbrand, the Batesville Area Arts Council, the City of Batesville, and across Southeastern Indiana. But the partnership does not focus only on the concert; to support programming leading up to the concert, ISO’s musicians engage with area schools and community leaders to promote the arts.

Events like the Star-Spangled Symphony benefit more than the arts. They enhance economic development by enabling smaller businesses to cross-sell to new groups of consumers who travel to communities to attend events. Arts act as a type of tourism department that most smaller communities cannot afford.

### The Interdependent Economy: Donations and Talent

In 2015, Hillenbrand launched One Campaign, a corporate initiative around four concepts to improve the communities where Hillenbrand operates: 1 day of service, 1 week of community partnership, 1 month of educational awareness, and 1 year of significant corporate contributions. As One Campaign grows, its focus has evolved from one-and-done volunteer projects to a platform linking business strategies with communities and aligning strategies with the United Nations Global Compact’s Sustainable Development Goals. In 2019, the company’s initiatives focused on quality education and helping employees foster educational partnerships in communities.

Employees at Hillenbrand in Batesville volunteer as tutors in a summer camp that teaches students about science, technology, engineering, arts, and mathematics—or STEAM. The camp serves students in kindergarten through sixth grade and links to Hillenbrand’s workforce talent pipeline.

We also provide opportunities for students in seventh through ninth grades to further their interest in manufacturing. For example, in Manufacturing Camp, a project that benefits a local not-for-profit organization, seventh graders provide backpacks full of school supplies to children in need across Southeastern Indiana. With oversight from company volunteers, students design a production line to fill backpacks with supplies. In doing so, they apply critical thinking to overcome everyday business obstacles, such as power outages, supply shortages, and tariffs. The students assemble 800–1,000 backpacks that are delivered to families in need in 16 counties surrounding Hillenbrand’s headquarters.

Donations of time and talent are important components of workforce-related programming and activities, but ultimately, they come with a price tag. Financial contributions or expenditures are often necessary to drive meaningful change, but if these are not strategic, a company risks sponsoring events with no meaningful link to the company’s strategic community and workforce initiatives.

Hillenbrand’s financial contributions align with the company’s values to pursue growth in the organization and to increase value for the community. We look for opportunities that are community-focused, mutually beneficial, and support growth through engagement.

Hillenbrand’s contributions are often mutualistic, benefitting both the company and the community. Consider how Manufacturing Camp works: Hillenbrand donates money to a not-for-profit organization working in the community, and then contributes time and volunteer talent to execute the task of filling and distributing the backpacks. Filled backpacks make their way to students in need in the region, who take their backpacks to area schools, where Hillenbrand recruits future employees.

### The Opioid Crisis and Rural Communities

Unfortunately, many communities are grappling with the opioid crisis. Through our partnership in legislative affairs with the local hospital, we found additional needs and startling statistics related to the opioid crisis and health, recovery, and housing in rural communities. Hillenbrand partnered with Margaret Mary Health in Batesville to determine how, as an anchor institution, Hillenbrand could join the conversation and play a role in leading solutions.

Clinicians in the hospital’s Addiction Services Program determined that while treating addiction is important, long-term success is rooted in improvements outside the clinical setting. The conditions that shape health—such as access to healthy food, housing, clothing, and often income—must be met to achieve long-term sustained changes in health behavior and are often difficult for a local company to address.

The hospital’s Addiction Services Program helps patients find employment, but many patients also experience housing insecurity. Lack of sober living facilities and homeless shelters and limited or nonexistent public transportation in rural communities are barriers to success.

Hillenbrand worked with the hospital to identify community stakeholders who could look for short- and long-term solutions to the barriers, and then hosted a roundtable conversation to gather different perspectives. The establishment of sober living facilities and additional housing for this population is still in its early stages, but sometimes having these challenging conversations in a rural community is the most difficult first step. Hillenbrand often serves as a convener for broader conversations in the community.

### Closing Skills Gaps

The challenges inherent in the location of Hillenbrand’s headquarters in rural Batesville are not unique to communities in the United States. Companies like Hillenbrand must think differently about how to attract and retain employees at home and abroad. We realize that developing and maintaining global partnerships to address changing workforce demographics will fuel business and community success.

Hillenbrand is partnering with Batesville High School and a school in Germany near one of our manufacturing sites, and creating opportunities for students in both countries to travel to each other’s sites, learn about the company, gain exposure to manufacturing facilities, and consider possible careers. Hillenbrand hopes ongoing collaboratives and hands-on activities will foster interest in manufacturing careers in the United States and abroad.

### Building a Sustainable Future

Since the early 1900s, Hillenbrand has embraced its role as an anchor institution in Batesville and in the communities it serves around the world. As an anchor, Hillenbrand has a responsibility and opportunity to strategically invest in communities to provide increased access to education and workforce training, hospitals and health and wellness programs, and cultural opportunities.

In July 2019, Hillenbrand announced its intent to acquire a similar-sized company based in nearby Cincinnati. Shortly after the news of the acquisition was released, community leaders were all asking one question: “Where will your headquarters be?” They were expecting Cincinnati. But we have not moved from Batesville.

For years, Hillenbrand has invested money, time, talent, and leadership to improve Batesville, Indiana, and surrounding communities, as well as all of the communities in which we operate abroad.

We have learned that no single effort will overcome the challenges that rural communities face in terms of workforce, education, and health. But having a strong community strategy and building rich relationships have helped Hillenbrand create a talent pipeline, build regional capacity, infuse arts and culture into everyday life, and improve the health of the people who live in the region. As CEO, I am pleased to share our commitment to help meet the needs of the present while making improvements for future generations. We believe the positive impacts of our people, products, and partnerships will help to enhance the environments in which we operate.

## Shakopee Mdewakanton Sioux Community Perspective

### Ancient Values and Business Success Spur Community Health and Economic Prosperity

Shakopee Mdewakanton Sioux Community (SMSC) is a federally recognized, sovereign Dakota tribal government located just southwest of Minneapolis–St. Paul, Minnesota. Our sovereign nation existed before the formation of the United States. Our ancestors have resided in this region for centuries.

Our tribe owns several businesses, or enterprises, first opening a tiny bingo hall in the 1980s that later became Little Six Casino. In 1992, our tribe opened Mystic Lake Casino Hotel, the premier gaming facility in the Midwest. SMSC enterprises have continued to grow and diversify over the years. Our tribe’s more than 15 enterprises include a fitness club and natural food market on the reservation, a nearby biomass energy facility, and a luxury hotel located adjacent to the Mall of America in Bloomington, Minnesota.

With more than 4,100 employees and nearly $177 million in annual payroll, our tribe is now the largest employer in Scott County, Minnesota. We also work with more than 2,000 vendors in a 25-mile radius and pay $300 million to vendors annually.

Like every responsible government, we provide for the well-being of our residents and employees and maintain important services and infrastructure, including roads, water and sewer systems, parks and green spaces, and emergency services. Unlike other governments, we fund these essential services with earnings generated from our enterprises. We do not have property, income, sales, or other tax revenue to sustain and grow our community and ensure that our community members are healthy and have opportunities to thrive.

Supporting the growth of our enterprises is very important to our tribe. As our enterprises have grown over the years, we have seen that our business success is closely tied to the success of neighboring communities and the wider region. When neighboring businesses and communities grow and thrive, so do our enterprises and our community. Therefore, we invest time and earnings back into the region and into other Native communities. We focus our investments on three strategic areas: our region and partners, our employees and community, and Indian Country.

### Our Values

Investing our business earnings into our communities to ensure that we all succeed, grow, and thrive together keeps both our enterprises and our communities strong. Our decisions are led by a commitment to our citizens, our culture, and our heritage.

Tribal Sovereignty: The Inherent Right of Tribes to Self-Governance and Self-Determination

The Dakota people have lived in the Minnesota and Mississippi River Valleys for thousands of years. The sovereignty of tribal governments predates—and is affirmed by—the U.S. Constitution and U.S. Supreme Court.

“The Congress shall have the power to … regulate commerce with foreign nations, and among the several states, and with the Indian tribes” (Article 1, Section 8, U.S. Constitution).

As sovereign nations, federally recognized tribes maintain a government-to-government relationship with all levels of government. Tribal members are citizens of their tribe, state, and the United States.

“Wo’ okiye” is the Dakota word for generosity and helping others. The Dakota people have a longstanding tradition of partnership and sharing resources, which we honor through our business practices; community investments in the region; a $500-million loan program across Indian Country; and our philanthropy program that has provided more than $350 million to other tribes, local governments, and nonprofit organizations.

The Dakota tradition of planning seven generations ahead also shapes our business and community decisions. We constantly consider how our decisions will impact people seven generations from now. This imperative influences our enterprise ventures and our stewardship of the environment.

### Investing in Our Region and Partners

SMSC partners with neighboring governments and organizations to benefit the region by addressing shared priorities, such as public safety, natural resources and the environment.

For example, SMSC partnered with Rahr Malting in 2007 to create a sustainable energy plant called Koda Energy. This combined heat and power plant is the only facility in the United States that burns exclusively natural, non-manmade materials. Using a suspension boiler for maximum efficiency to burn only renewable products, its rate of heat conversion is approximately 87%, which is substantially higher than that of coal (63%). This renewable and sustainable source of energy produces electricity and other forms of power.

The jointly owned facility continues the tribe’s tradition of stewarding the environment and earning revenue from selling excess energy.

Governance Structure

We are charged with promoting the health, education, and welfare of our tribal members now and for generations to come. This includes making decisions that shape SMSC’s role as an employer and member of the broader community.

The highest governing body of SMSC is the General Council, comprised of all enrolled members of our tribe 18 years of age and older. This council meets monthly to discuss important issues, make decisions and set policies, and approve the annual budget of our community. The General Council also elects three members of the Business Council (chair, vice-chair, and secretary/treasurer) and members of other governing bodies.

The Business Council is responsible for running the day-to-day operations of the tribe and implementing the decisions of the General Council.

Clean water is essential to our communities. SMSC and the City of Prior Lake worked together to build a water treatment plant for both communities, treating up to 3.5-million gallons of water per day for use by the tribe and the city. SMSC provided $22.5 million for the project, and the city invested $2.2 million for the equipment necessary to deliver treated water now and in the future. The plant is designed for future expansion as each community grows. By sharing the facility, we reduce redundancies and achieve significant savings for both communities.

Our tribal government is also committed to collaborating and communicating with neighboring governments in Scott County. For example, the Scott County Association for Leadership and Efficiency (SCALE), developed in 2003, is an award-winning local government collaboration between SMSC; Scott County; and the cities, schools, and townships in Scott County. SCALE welcomes entities as equal and voluntary partners who work together to serve the region’s growing population more efficiently and effectively. SCALE’s initiatives and projects have benefited SMSC and the region, saving all entities money by pooling resources and avoiding redundancies.

Following the success of SCALE, SMSC and its neighbors in Scott County and the Cities of Prior Lake and Shakopee formed the Intergovernmental Working Group (IWG) in 2012. IWG focuses on specific issues, such as land development rights. Like SCALE, IWG provides a forum for governments to come together and find solutions to shared challenges.

### Investing in Our Employees and Community

The success of our enterprises is the result of contributions made by many people. Our tribe recognizes the importance of our people, including employees; we take pride in being a good employer that employees are proud to work for.

SMSC demonstrates its values and its appreciation for members and employees by providing them with a comprehensive benefits package and a wide range of services. Employees receive medical and dental insurance and a health flex spending account. They have access to the on-site Mystic Clinic and Shakopee Dakota Clinic, as well as to the tribe’s vision and dental clinics. Employees receive discounts at our fitness center, Dakotah! Sport and Fitness, and our natural food market. Beyond health benefits, team members have access to a 401(k) retirement plan, tuition reimbursement, life and disability insurance, weekly pay, free beverages while working, and free uniforms and laundering. Employees at SMSC and its enterprises receive a 50% discount at Playworks, an on-site childcare and early childhood education facility. Many employees also receive access to free transportation to and from work through a variety of options, including a partnership with the Metro Valley Transit Authority.

Part-time employees receive medical insurance for those working an average of 30 or more hours per week, a 401(k) retirement plan, discounts on health risk assessments and health education, and a discount on membership at Dakotah! Sport and Fitness.

Our employees are some of our biggest advocates, and many stay with us for a long time. The average tenure for SMSC employees is 8 years, which is twice the national average.

### Investing in Indian Country

As a Native American tribe, SMSC places particular importance on collaborating with and supporting other tribes and Native American communities. Our investments aim to strengthen individual tribal communities and all of Indian Country.

Many tribes struggle economically; solutions, such as building and maintaining enterprises, are expensive. A lack of economic development means many Native American communities are deemed high risk from a loan perspective, and tribal governments have difficulty obtaining bank loans to cover such investments. To help meet this need, SMSC’s loan program has provided more than $500 million to help spur economic development across Indian Country. The loans help tribes start up and expand enterprises that provide jobs and income for their citizens and enhance their region’s economy. The loans also provide interest return for our own tribal community. For example, SMSC funded Red Lake Nation’s casino and hotel in Warroad, Minnesota, with a $27 million loan. The facility opened in 2014 with a state-of-the-art gaming floor and hotel, drawing in new visitors to their reservation and providing about 100 new jobs for tribal and nontribal members in the Warroad area.

As our enterprises have grown over the years, we’ve seen that our business success is closely tied to the success of the wider region. When neighboring businesses and communities grow and thrive, so do our enterprises and our own community. Therefore, we invest time and earnings back into the region….

The loss of traditional foods and extreme poverty have caused many Native Americans to suffer from poor or inadequate diets. This has led to obesity, diabetes, and other health problems. In fact, Native Americans are twice as likely as the rest of the U.S. population to have nutrition-related health problems.

To improve nutrition and restore healthful diets among Native Americans in our community and nationally, we established an organic garden and natural food market and launched Seeds of Native Health, a $10-million national philanthropic campaign including grantmaking, advocacy, and research. For example, we contributed $80,000 toward the implementation of the Navajo Nation’s “junk food” tax, which leveraged an additional $262,000 from three other funders. The Seeds of Native Health campaign collaborated with MAZON: A Jewish Response to Hunger, to jointly fund the Indigenous Food and Agriculture Initiative’s model tribal agriculture and food code project. The partnership made the policy research project possible and involved a new organization in efforts to improve Native dietary health.

### Building a Sustainable Future

Our tribe has forged many relationships, strengthened partnerships, and made investments with the goals of serving our citizens and our Dakota values and of helping the broader community reach their goals. By investing in our region, partners, employees, and community and in other sovereign Native nations, we strengthen our own enterprises and strengthen our people and communities.

Our traditions of “wo’ okiye,” or helpfulness, and of planning seven generations ahead inform our decisions and contribute to the success of our region and of Indian Country as a whole. Not only are these important values, but our tribal community and enterprises have succeeded thanks in part to these traditions. As a tribal government and an owner and operator of many successful enterprises, we have seen firsthand how investing in the broader community benefits our own community and enterprises, which—like many businesses—brings value to our region. Our success is interconnected and shared.

We have seen this interconnection and shared values when building partnerships with competitors, providing high-quality employee benefits and training programs, and helping other Native communities access capital for community development. Our story underscores how putting values into action and building up other governments, businesses, and communities can help everyone achieve great things.