# APPENDIX C References

## Message From Alex M. Azar II

p. iii: Low-income Americans continue to suffer more severe illness from COVID-19. Koma, W., Artiga, S., Neuman, T., Claxton, G., Rae, M., Kates, J., & Michaud, J. (2020, May 7). Low-income and communities of color at higher risk of serious illness if infected with coronavirus. Retrieved from https://www.kff.org/coronavirus-covid-19/issue-brief/low-income-and-communities-of-color-at-higher-risk-of-serious-illness-if-infected-with-coronavirus/

## Foreword From the Surgeon General

p. xxvii: The success of businesses depends on a healthy and productive workforce, and businesses pay about 20% of the nation’s medical care costs. Centers for Medicare & Medicaid Services. (n.d.). National health expenditures 2017 highlights. Retrieved from https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/NationalHealthExpendData/Downloads/highlights.pdf

## Chapter 1 The U.S. Health Disadvantage and Why It Matters to Business

p. 3: Americans’ assumptions about health and healthcare. Avendano, M., & Kawachi, I. (2014). Why do Americans have shorter life expectancy and worse health than people in other high-income countries? Annual Review of Public Health, 35, 307–325 ; Dickman, S. L., Himmelstein, D. U., & Woolhandler, S. (2017). Inequality and the health-care system in the U.S.A. Lancet, 389(10077), 1431–1441 ; 28402825 Global Burden of Disease 2017 Mortality Collaborators. (2018). Global, regional, and national age-sex-specific mortality and life expectancy, 1950–2017: A systematic analysis for the Global Burden of Disease Study 2017. Lancet, 392(10159), 1684–1735 ; 30496102 Mossialos, E., Djordjevic, A., Osborn, R., & Sarnak, D. (Eds.). (2017). International profiles of health care systems. New York, NY: The Commonwealth Fund ; and Woolf, S. H., & Aron, L. (Eds.). (2013). U.S. health in international perspective: Shorter lives, poorer health. Panel on Understanding Cross-National Health Differences Among High-Income Countries. National Research Council, Committee on Population, Division of Behavioral and Social Sciences and Education, and Board on Population Health and Public Health Practice, Institute of Medicine. Washington, DC: The National Academies Press.
p. 3: People in the United States have poorer health and experience greater health inequity. Avendano, M., & Kawachi, I. (2014). Why do Americans have shorter life expectancy and worse health than people in other high-income countries? Annual Review of Public Health, 35, 307–325 ; Global Burden of Disease 2017 Mortality Collaborators. (2018). Global, regional, and national age-sex-specific mortality and life expectancy, 1950–2017: A systematic analysis for the Global Burden of Disease Study 2017. Lancet, 392(10159), 1684–1735 ; 30496102 Muennig, P. A., Reynolds, M., Fink, D. S., Zafari, Z., & Geronimus, A. T. (2018). America’s declining well-being, health, and life expectancy: Not just a White problem. American Journal of Public Health, 108(12), 1626–1631 ; and 30252522 Woolf, S. H., & Aron, L. (Eds.). (2013). U.S. health in international perspective: Shorter lives, poorer health. Panel on Understanding Cross-National Health Differences Among High-Income Countries. National Research Council, Committee on Population, Division of Behavioral and Social Sciences and Education, and Board on Population Health and Public Health Practice, Institute of Medicine. Washington, DC: The National Academies Press.
p. 3: Difference in how long Americans live and how healthy they are. Avendano, M., Kok, R., Glymour, M., Berkman, L., Kawachi, I., Kunst, A., & Mackenbach, J. (2010). Do Americans have higher mortality than Europeans at all levels of the education distribution?: A comparison of the United States and 14 European countries. In E. M. Crimmins, S. H. Preston, & B. Cohen (Eds.), International differences in mortality at older ages: Dimensions and sources (pp. 313–332). Washington, DC: National Academies Press.
p. 3: Americans cannot fully access the U.S. healthcare system. Dickman, S. L., Himmelstein, D. U., & Woolhandler, S. (2017). Inequality and the health-care system in the U.S.A. Lancet, 389(10077), 1431–1441 ; and 28402825 Mossialos, E., Djordjevic, A., Osborn, R., & Sarnak, D. (Eds.). (2017). International profiles of health care systems. New York, NY: The Commonwealth Fund.
p. 3: 28.9 million non-elderly Americans lacked health insurance in 2018. Tolbert, J., Orgera, K., & Damico, A. (2020, November). Key facts about the uninsured population. Retrieved from https://www.kff.org/uninsured/issue-brief/key-facts-about-the-uninsured-population/
p. 3: A person’s ability to receive quality healthcare in America is not universal. Davis, K., & Ballreich, J. (2014). Equitable access to care—How the United States ranks internationally. New England Journal of Medicine, 371(17), 1567–1570 ; and Osborn, R., Squires, D., Doty, M. M., Sarnak, D. P., & Schneider, E. C. (2016, November 16). In new survey of 11 countries, U.S. adults still struggle with access to and affordability of health care. Retrieved from https://www.commonwealthfund.org/publications/journal-article/2016/nov/new-survey-11-countries-us-adults-still-struggle-access-and
p. 3: Healthcare expenditures in the United States vs. the average healthcare expenditures of member nations of OECD. Organisation for Economic Co-operation and Development. (2019). Health at a glance 2019: OECD indicators. Paris, France: OECD Publishing. Retrieved from 10.1787/4dd50c09-en
pp. 3–4: OECD countries spend less on healthcare than the United States but have healthier populations and greater life expectancies; and the paradox. Papanicolas, I., Woskie, L. R., & Jha, A. K. (2018). Health care spending in the United States and other high-income countries. JAMA, 319(10), 1024–1039.29536101
p. 4: Figure 1.1. Source: Adapted from page 151 of Organisation for Economic Co-operation and Development. (2019). Health at a glance 2019: OECD indicators. Paris, France: OECD Publishing. Retrieved from 10.1787/4dd50c09-en. Note B: Page 154 in Organisation for Economic Co-operation and Development. (2019). Health at a glance 2019: OECD indicators. Paris, France: OECD Publishing. Retrieved from 10.1787/4dd50c09-en
pp. 4–5: Conditions that shape health are outside the clinic. Braveman, P., & Egerter, S. (2008). Overcoming obstacles to health. Princeton, NJ: Robert Wood Johnson Foundation Commission to Build a Healthier America ; Commission on Social Determinants of Health. (2008). Closing the gap in a generation: Health equity through action on the social determinants of health. Retrieved from https://www.who.int/social_determinants/thecommission/finalreport/en/ ; and Woolf, S. H., & Schoomaker, H. (2019). Life expectancy and mortality rates in the United States, 1959–2017. JAMA, 322(20), 1996–2016.31769830
p. 5: Healthcare is estimated to account for only 10–20% of health outcomes. Hood, C. M., Gennuso, K. P., Swain, G. R., & Catlin, B. B. (2016). County health rankings: Relationships between determinant factors and health outcomes. American Journal of Preventive Medicine, 50(2), 129–135.26526164
p. 5: U.S. life expectancy is decreasing for the first time in generations. Bernstein, L. (2018, November 21). U.S. life expectancy declines again, a dismal trend not seen since World War I. Washington Post. Retrieved from https://www.washingtonpost.com/national/health-science/us-life-expectancy-declines-again-a-dismal-trend-not-seen-since-world-war-i/2018/11/28/ae58bc8c-f28c-11e8-bc79-68604ed88993_story.html ; and McKay, B. (2018, November 29). U.S. life expectancy falls further. Wall Street Journal. Retrieved from https://www.wsj.com/articles/u-s-life-expectancy-falls-further-1543467660
pp. 5–6: U.S. life expectancy decreased for three consecutive years. Murphy, S. L., Xu, J. Q., Kochanek, K. D., & Arias, E. (2018). Mortality in the United States, 2017. NCHS Data Brief, 1–8 ; and National Center for Health Statistics. (2018). Health, United States, 2017: With special feature on mortality. Hyattsville, MD: National Center for Health Statistics.
p. 6: Life expectancy continues to increase in other wealthy countries. Acciai, F., & Firebaugh, G. (2017). Why did life expectancy decline in the United States in 2015? A gender-specific analysis. Social Science and Medicine, 190, 174–180 ; 28865253 Ho, J. Y., & Hendi, A. S. (2018). Recent trends in life expectancy across high income countries: Retrospective observational study. BMJ, 362, k2562 ; 30111634 Murphy, S. L., Xu, J. Q., Kochanek, K. D., & Arias, E. (2018). Mortality in the United States, 2017. NCHS Data Brief, 328, 1–8 ; and National Center for Health Statistics. (2018). Health, United States, 2017: With special feature on mortality. Hyattsville, MD: National Center for Health Statistics.
p. 6: The downturn in the health status of Americans is not new. Global Burden of Disease 2017 Mortality Collaborators. (2018). Global, regional, and national age-sex-specific mortality and life expectancy, 1950–2017: A systematic analysis for the Global Burden of Disease Study 2017. Lancet, 392(10159), 1684–1735 ; 30496102 Muennig, P. A., & Glied, S. A. (2010). What changes in survival rates tell us about U.S. health care. Health Affairs, 29(11), 2105–2113 ; 20930036 Raleigh, V. S. (2019). Trends in life expectancy in EU and other OECD countries: Why are improvements slowing? (OECD Working Paper No. 108). Retrieved from https://www.oecd-ilibrary.org/social-issues-migration-health/trends-in-life-expectancy-in-eu-and-other-oecd-countries_223159ab-en ; Woolf, S. H., & Aron, L. (2013). The U.S. health disadvantage relative to other high-income countries: Findings from a National Research Council/Institute of Medicine report. JAMA, 309(8), 771–772 ; and 23307023 Woolf, S. H., & Aron, L. (2018). Failing health of the United States. BMJ, 360, k496.29437654
p. 6: Figure 1.2. Source: Data obtained from The World Bank. (n.d.). Life expectancy at birth, total (years). Retrieved from https://data.worldbank.org/indicator/sp.dyn.le00.in
p. 7: Table 1.1. Source: Table 14 in Organisation for Economic Co-operation and Development. (2018). Health, United States, 2017—Data finder. Retrieved from https://www.cdc.gov/nchs/hus/contents2017.htm#014. Note A: Woolf, S. H., & Aron, L. (Eds.). (2013). U.S. health in international perspective: Shorter lives, poorer health. Panel on Understanding Cross-National Health Differences Among High-Income Countries. National Research Council, Committee on Population, Division of Behavioral and Social Sciences and Education, and Board on Population Health and Public Health Practice, Institute of Medicine. Washington, DC: The National Academies Press. Note B: IndexMundi. (n.d.). Canada—life expectancy at birth. Retrieved from https://www.indexmundi.com/facts/canada/life-expectancy-at-birth
p. 7: Figure 1.3. Source: Centers for Disease Control and Prevention, National Center for Health Statistics. (2020). Underlying cause of death 1999–2018 (from the multiple cause of death files, 1999–2018, as compiled from data provided by the 57 vital statistics jurisdictions through the Vital Statistics Cooperative Program). Retrieved from http://wonder.cdc.gov/ucd-icd10.html
p. 8: The U.S. health disadvantage extends beyond lower life expectancy. Avendano, M., & Kawachi, I. (2014). Why do Americans have shorter life expectancy and worse health than people in other high-income countries? Annual Review of Public Health, 35, 307–325 ; Buttorff, C., Ruder, T., & Bauman, M. (2017). Multiple chronic conditions in the United States. Retrieved from http://www.fightchronicdisease.org/sites/default/files/TL221_final.pdf ; Goldman, N., Glei, D. A., & Weinstein, M. (2018). Declining mental health among disadvantaged Americans. Proceedings of the National Academy of Sciences of the United States of America, 115(28), 7290–7295 ; 29915079 Salomon, J. A., Nordhagen, S., Oza, S., & Murray, C. J. (2009). Are Americans feeling less healthy? The puzzle of trends in self-rated health. American Journal of Epidemiology, 170(3), 343–351 ; 19564169 Toossi, M. (2002). A century of change: the U.S. labor force, 1950–2050. Monthly Labor Review, 15–28 ; Toossi, M. (2012). Employment outlook: 2010–2020. Labor force projection to 2020: a more slowly growing workforce. Monthly Labor Review, 43–64 ; Weinberger, A. H., Gbedemah, M., Martinez, A. M., Nash, D., Galea, S., & Goodwin, R. D. (2018). Trends in depression prevalence in the U.S.A. from 2005 to 2015: Widening disparities in vulnerable groups. Psychological Medicine, 48(8), 1308–1315 ; 29021005 Woolf, S. H., & Aron, L. (Eds.). (2013). U.S. health in international perspective: Shorter lives, poorer health. Panel on Understanding Cross-National Health Differences Among High-Income Countries. National Research Council, Committee on Population, Division of Behavioral and Social Sciences and Education, and Board on Population Health and Public Health Practice, Institute of Medicine. Washington, DC: The National Academies Press ; and Zack, M. M., Moriarty, D. G., Stroup, D. F., Ford, E. S., & Mokdad, A. H. (2004). Worsening trends in adult health-related quality of life and self-rated health—United States, 1993–2001. Public Health Reports, 119(5), 493–505.15313113
p. 8: Footnote. Labor participation in 2020: Chart 2 in U.S. Bureau of Labor Statistics. (2020, July 2). Charting the labor market: Data from the Current Population Survey (CPS). Retrieved from https://www.bls.gov/web/empsit/cps_charts.pdf
p. 8: Figure 1.4. Source: Table 4 in Toossi, M. (2002). A century of change: the U.S. labor force, 1950–2050. Monthly Labor Review, 15–28 ; and Table 3 in Toossi, M. (2012). Employment outlook: 2010–2020. Labor force projection to 2020: a more slowly growing workforce. Monthly Labor Review, 43–64.
pp. 8–9: The U.S. health disadvantage affects much of the population. Crimmins, E. M., Preston, S. H., & Cohen, B. (Eds.). (2011). Explaining divergent levels of longevity in high-income countries. Washington, DC: National Academies Press ; and Woolf, S. H., & Aron, L. (Eds.). (2013). U.S. health in international perspective: Shorter lives, poorer health. Panel on Understanding Cross-National Health Differences Among High-Income Countries. National Research Council, Committee on Population, Division of Behavioral and Social Sciences and Education, and Board on Population Health and Public Health Practice, Institute of Medicine. Washington, DC: The National Academies Press.
p. 9: The U.S. health disadvantages are diverse. Woolf, S. H., & Aron, L. (2013). The U.S. health disadvantage relative to other high-income countries: Findings from a National Research Council/Institute of Medicine report. JAMA, 309(8), 771–772.23307023
p. 9: Outcomes from health disadvantages persist despite America’s large investments in healthcare. Papanicolas, I., Woskie, L. R., & Jha, A. K. (2018). Health care spending in the United States and other high-income countries. JAMA, 319(10), 1024–1039.29536101
p. 9: Estimates suggest that the U.S. health disadvantage will continue to worsen. Kontis, V., Bennett, J. E., Mathers, C. D., Li, G., Foreman, K., & Ezzati, M. (2017). Future life expectancy in 35 industrialised countries: Projections with a Bayesian model ensemble. Lancet, 389(10076), 1323–1335.28236464
p. 9: The United States differs from other wealthy countries in five areas. Avendano, M., & Kawachi, I. (2014). Why do Americans have shorter life expectancy and worse health than people in other high-income countries? Annual Review of Public Health, 35, 307–325 ; Crimmins, E. M., Preston, S. H., & Cohen, B. (Eds.). (2011). Explaining divergent levels of longevity in high-income countries. Washington, DC: National Academies Press ; and Woolf, S. H., & Aron, L. (Eds.). (2013). U.S. health in international perspective: Shorter lives, poorer health. Panel on Understanding Cross-National Health Differences Among High-Income Countries. National Research Council, Committee on Population, Division of Behavioral and Social Sciences and Education, and Board on Population Health and Public Health Practice, Institute of Medicine. Washington, DC: The National Academies Press.
p. 9: Social and economic factors. Desilver, D. (2017). U.S. students’ academic achievement still lags that of their peers in many other countries. Retrieved from https://www.pewresearch.org/fact-tank/2017/02/15/u-s-students-internationally-math-science/
p. 10: Social and physical environments. Forsyth, A., & Southworth, M. (2008). Cities afoot—Pedestrians, walkability and urban design. Journal of Urban Design, 13, 1–3 ; Southworth, M. (2005). Designing the walkable city. Journal of Urban Planning and Development, 131, 246–257 ; and Woolf, S. H., & Aron, L. (Eds.). (2013). U.S. health in international perspective: Shorter lives, poorer health. Panel on Understanding Cross-National Health Differences Among High-Income Countries. National Research Council, Committee on Population, Division of Behavioral and Social Sciences and Education, and Board on Population Health and Public Health Practice, Institute of Medicine. Washington, DC: The National Academies Press.
p. 10: Individual behaviors. Woolf, S. H., & Aron, L. (Eds.). (2013). U.S. health in international perspective: Shorter lives, poorer health. Panel on Understanding Cross-National Health Differences Among High-Income Countries. National Research Council, Committee on Population, Division of Behavioral and Social Sciences and Education, and Board on Population Health and Public Health Practice, Institute of Medicine. Washington, DC: The National Academies Press.
p. 10: Footnote. Contributions of higher rates of smoking from decades ago: Preston, S. H., Glei, D. A., & Wilmoth, J. R. (2010). Contribution of smoking to international differences in life expectancy. In S. H. Preston & B. Cohen (Eds.), International differences in mortality at older ages: Dimensions and sources (pp. 105–131). Washington, DC: National Academies Press.
p. 10: Healthcare. Dickman, S. L., Himmelstein, D. U., & Woolhandler, S. (2017). Inequality and the health-care system in the U.S.A. Lancet, 389(10077), 1431–1441 ; and 28402825 Mossialos, E., Djordjevic, A., Osborn, R., & Sarnak, D. (Eds.). (2017). International profiles of health care systems. New York, NY: The Commonwealth Fund.
p. 10: Spending on programs that provide direct cash transfer and healthcare-related costs (e.g., Medicare and Medicaid) increased by 162%. The Concord Coalition. (2018, July 2). A troubling trend in federal investment spending. Retrieved from https://www.concordcoalition.org/issue-brief/troubling-trend-federal-investment-spending
p. 10: Prioritizing spending on social services over spending on healthcare. Bradley, E. H., Canavan, M., Rogan, E., Talbert-Slagle, K., Ndumele, C., Taylor, L., & Curry, L. A. (2016). Variation in health outcomes: The role of spending on social services, public health, and health care, 2000–09. Health Affairs, 35(5), 760–768 ; and 27140980 Bradley, E. H., Elkins, B. R., Herrin, J., & Elbel, B. (2011). Health and social services expenditures: Associations with health outcomes. BMJ Quality & Safety, 20(10), 826–31.
p. 10: Racism and bias are an important contributing cause of poor health outcomes for people of color in the United States. Williams, D. R., Lawrence, J. A., & Davis, B. A. (2019). Racism and health: Evidence and needed research. Annual Review of Public Health, 40, 105–125.
p. 10: Factors that contribute individually and collectively to poorer health outcomes. Paradies, Y., Ben, J., Denson, N., Elias, A., Priest, N., Pieterse, A., … Gee, G. (2015). Racism as a determinant of health: A systematic review and meta-analysis. PLoS One, 10(9), e0138511.26398658
p. 10: Racism and bias in the diagnosis and treatment of disease contributes to poorer health outcomes. Cain, V. S., & Kington, R. S. (2003). Investigating the role of racial/ethnic bias in health outcomes. American Journal of Public Health, 93(2), 191–192 ; 12554567 Simon, S., & Ho, P. M. (2020). Ethnic and racial disparities in acute myocardial infarction. Current Cardiology Reports 22(9), 88 ; and 32648143 Smedley, B. D., Stith, A. Y., & Nelson, A. R. (Eds.). (2002). Unequal treatment: Confronting racial and ethnic disparities in health care. Washington, DC: National Academies Press.
pp. 10: Unhealthy behaviors contribute significantly to disease and death. Institute of Medicine and National Research Council. (2015). Measuring the risks and causes of premature death: Summary of workshops. Washington, DC: The National Academies Press ; Mokdad, A. H., Marks, J. S., Stroup, D. F., & Gerberding, J. L. (2004). Actual causes of death in the United States, 2000. JAMA, 291(10), 1238–1245 ; and 15010446 Mokdad, A. H., Marks, J. S., Stroup, D. F., Gerberding, J. L. (2005). Correction: Actual causes of death in the United States, 2000. JAMA, 293(3), 293–294.15657315
p. 11: Physical and social environments influence unhealthy behaviors that contribute to disease and death. Woolf, S. H., & Braveman, P. (2011). Where health disparities begin: The role of social and economic determinants—and why current policies may make matters worse. Health Affairs, 30(10), 1852–1859.21976326
p. 11: Social and economic factors rank among the most influential drivers of health. Braveman, P., Acker, J., Arkin, E., Proctor, D., Gillman, A., McGeary, K. A., & Mallya, G. (2018). Wealth matters for health equity (Executive Summary). Princeton, NJ: Robert Wood Johnson Foundation ; and Braveman, P. A., Cubbin, C., Egerter, S., Williams, D. R., & Pamuk, E. (2010). Socioeconomic disparities in health in the United States: What the patterns tell us. American Journal of Public Health, 100(Suppl 1):S186–S196.20147693
p. 11: Decisions on public policies and spending greatly influence the other four areas. Avendano, M., & Kawachi, I. (2014). Why do Americans have shorter life expectancy and worse health than people in other high-income countries? Annual Review of Public Health, 35, 307–325.
p. 11: Mounting stresses contribute to poor health. Avendano, M., & Kawachi, I. (2014). Why do Americans have shorter life expectancy and worse health than people in other high-income countries? Annual Review of Public Health, 35, 307–325 ; Benach, J., Vives, A., Amable, M., Vanroelen, C., Tarafa, G., & Muntaner, C. (2014). Precarious employment: Understanding an emerging social determinant of health. Annual Review of Public Health, 35, 229–253 ; Halliday, T. J. (2017). Earnings growth and movements in self-reported health. Review of Income and Wealth, 63(4), 760–776 ; Meraya, A. M., Dwibedi, N., Tan, X., Innes, K., Mitra, S., & Sambamoorthi, U. (2018). The dynamic relationships between economic status and health measures among working-age adults in the United States. Health Economics, 27(8), 1160–1174 ; and 29667770 Ruckert, A., & Labonte, R. (2017). Health inequities in the age of austerity: The need for social protection policies. Social Science and Medicine, 187, 306–311.28359581
p. 12: Costs of unplanned work absences from diabetes. American Diabetes Association. (2018). Economic costs of diabetes in the U.S. in 2017. Diabetes Care, 41(5), 917–928 ; and 29567642 Gallup-Share Care Wellbeing Index. (2017, November 13). The cost of diabetes in the U.S.: Economic and well-being impact. Retrieved from https://wellbeingindex.sharecare.com/diabetes-us-economic-well-being-impact/
p. 12: Table 1.2. Source: American Diabetes Association. (2018). Economic costs of diabetes in the U.S. in 2017. Diabetes Care, 41(5), 917–928.29567642
p. 12: Factors that affect the health status of workers and their productivity on the job. Bipartisan Policy Center and de Beaumont Foundation. (2019). Good health is good business: The value proposition of partnerships between businesses and governmental public health agencies to improve community health. Washington, DC: Bipartisan Policy Center ; and Kindig, D., Isham, G., & Siemering, K. Q. (2013). The business role in improving health: Beyond social responsibility. Washington, DC: Institute of Medicine. Retrieved from 10.31478/201308b
p. 12: Likelihood of outcomes in workers with less education or income. Susser, P., & Ziebarth, N. R. (2016). Profiling the U.S. sick leave landscape: Presenteeism among females. Health Services Research, 51(6), 2305–2317.26947427
pp. 12–13: Lower income adds to psychological distress. Blackwell, D. L., & Villarroel, M. A. (2017). Table A-8a. Age-adjusted percentages (with standard errors) of feelings of nervousness, feelings of restlessness, and serious psychological distress among adults aged 18 and over, by selected characteristics: United States, 2017. Retrieved from https://ftp.cdc.gov/pub/Health_Statistics/NCHS/NHIS/SHS/2017_SHS_Table_A-8.pdf
p. 13: Impact of the opioid epidemic. Barbieri, M. (2019). The contribution of drug-related deaths to the U.S. disadvantage in mortality. International Journal of Epidemiology, 48(3), 945–953 ; and 30597015 Florence, C. S., Zhou, C., Luo, F., & Xu, L. (2016). The economic burden of prescription opioid overdose, abuse, and dependence in the United States, 2013. Medical Care, 54(10), 901–906.27623005
p. 13: Footnote. Increase in opioid prescriptions in other countries: Ho, J. Y., & Hendi, A. S. (2018). Recent trends in life expectancy across high income countries: Retrospective observational study. BMJ, 362, k2562.30111634 Increase in drug overdose deaths in the United States: Barbieri, M. (2019). The contribution of drug-related deaths to the U.S. disadvantage in mortality. International Journal of Epidemiology, 48(3), 945–953.30597015
p. 13: Box 1.1a. Well Being In the Nation Network. (n.d.). Theory of change. Retrieved from https://winnetwork.org/win-theory-of-change ; and Well Being In the Nation Network. (n.d.). Vital conditions. Retrieved from https://winnetwork.org/vital-conditions
p. 13: Box 1.1a note. ReThink Health. (2019). Negotiating a well-being portfolio. Retrieved from https://www.rethinkhealth.org/wp-content/uploads/2019/10/RTH-PortfolioSummary_Overview-Definitions-NatProfile.pdf
pp. 14–15: Box 1.1b note. Graphic is adapted with permission from The Rippel Foundation, All Rights Reserved.
p. 16. Figure 1.5. Blackwell, D. L., & Villarroel, M. A. (2017). Table A-10a. Age-adjusted percentages (with standard errors) of difficulties in physical functioning among adults aged 18 and over, by selected characteristics: United States, 2017. Retrieved from https://ftp.cdc.gov/pub/Health_Statistics/NCHS/NHIS/SHS/2017_SHS_Table_A-10.pdf
p. 17: Box 1.2. Webber, A., & Mercure, S. (2010). Improving population health: The business community imperative. Preventing Chronic Disease, 7(6), A121.20950528
pp. 17–18: Adverse conditions that affect the health of a community also stifle upward mobility and the well-being of communities. Boushey, H., DeLong, B., & Steinbaum, M. (Eds.). (2016). After Piketty: The agenda for economics and inequality. Cambridge, MA: Harvard University Press.
p. 18: High prevalence of obesity and other health problems in active-duty military personnel and recruits. Maxey, H., Bishop-Josef, S., & Goodman, B. (2018, October). Unhealthy and unprepared: National security depends on promoting healthy lifestyles. Retrieved from https://www.strongnation.org/articles/737-unhealthy-and-unprepared

## Chapter 2 How Neighborhoods Shape Health and Opportunity

p. 26: Opportunity looks different in many communities across the United States. Acevedo-Garcia, D., McArdle, N., Hardy, E. F., Crisan, U. I., Romano, B., Norris, D., … Reece, J. (2014). The child opportunity index: improving collaboration between community development and public health. Health Affairs, 33(11), 1948–1957.25367989
p. 27: Box 2.1. Source: Unless cited otherwise, data are from the Child Opportunity Index 2.0 (diversitydatakids.org, n.d.). Concentrated poverty in neighborhoods and schools is associated with poor physical and mental health, as well as low student graduation rates and future earnings: Acevedo-Garcia, D., McArdle, N., Hardy, E. F., Crisan, U. I., Romano, B., Norris, D., … Reece, J. (2014). The child opportunity index: improving collaboration between community development and public health. Health Affairs, 33(11), 1948–1957 ; and 25367989 Acevedo-Garcia, D., Noelke, C., & McArdle, N. (2020, January). The geography of child opportunity: Why neighborhoods matter for equity—First findings from the Child Opportunity Index 2.0. Retrieved from http://new.diversitydatakids.org/sites/default/files/file/ddk_the-geography-of-child-opportunity_2020v2_0.pdf. Lack of access to healthy food is associated with health problems and obesity in children: Acevedo-Garcia, D., McArdle, N., Hardy, E. F., Crisan, U. I., Romano, B., Norris, D., … Reece, J. (2014). The child opportunity index: improving collaboration between community development and public health. Health Affairs, 33(11), 1948–1957.25367989
p. 28: Neighborhood features influence health and well-being through biologic and social mechanisms. Arcaya, M. C., Tucker-Seeley, R. D., Kim, R., Schnake-Mahl, A., So, M., & Subramanian, S. V. (2016). Research on neighborhood effects on health in the United States: A systematic review of study characteristics. Social Science and Medicine, 168, 16–29 ; and 27637089 Morenoff, J. D., & Lynch, J. W. (2004). What makes a place healthy? Neighborhood influences on racial/ethnic disparities in health over the life course. In: N. B. Anderson, R. A. Bulatao, & B. Cohen (Eds.), Critical perspectives on racial and ethnic differences in health in late life (pp. 406–449). Washington, DC: The National Academies Press.
p. 28: Social and environmental conditions in the neighborhoods in which children live and grow shape their health and affect their life chances. Hood, C. M., Gennuso, K. P., Swain, G. R., & Catlin, B. B. (2016). County health rankings: Relationships between determinant factors and health outcomes. American Journal of Preventive Medicine, 50(2), 129–135.26526164
p. 28: Immediate living environment of families is a powerful influence on children’s prospects in adulthood. Chetty, R., Friedman, J. N., Hendren, N., Jones, M. R., & Porter, S. R. (2018). The Opportunity Atlas: Mapping the childhood roots of social mobility. Retrieved from https://ideas.repec.org/p/cen/wpaper/18-42.html
p. 28: Absence of certain features diminishes life chances for children who grow up in low opportunity neighborhoods. Galster, G. (2012). The mechanism(s) of neighbourhood effects: Theory, evidence, and policy implications. In: M. V. Ham, D. Manley, N. Bailey, L. Simpson, & D. Maclennan (Eds.), Neighbourhood effects research: New perspectives (pp. 23–56). Dordrecht, Netherlands: Springer.
p. 29: Box. 2.2. Color infiltration: Digital Scholarship Lab, University of Richmond. (n.d.). Mapping inequality: Redlining in New Deal America [Map of Brooklyn, NY, D8]. Retrieved from https://dsl.richmond.edu/panorama/redlining/#loc=14/40.638/-74.093&city=brooklyn-ny&area=D8. HOLC recommendations: Digital Scholarship Lab, University of Richmond. (n.d.). Mapping inequality: Redlining in New Deal America [Map of cities that HOLC graded]. Retrieved from https://dsl.richmond.edu/panorama/redlining/#loc=5/37.8/-97.9. Addressing the needs of only the formerly redlined neighborhoods would likely miss many of the people who most directly experienced the decades of disinvestment: Perry, A. M., & Harshbarger, D. (2019, October 14). America’s formerly redlined neighborhoods have changed, and so must solutions to rectify them. Retrieved from https://www.brookings.edu/research/americas-formerly-redlines-areas-changed-so-must-solutions/. Current geographic patterns of concentrated disadvantage and prevalence of health problems closely follow the redlining maps of the past: Reece, J., Martin, M., Bates, J., Golden, A., Mailman, K., & Nimps, R. (2015). History matters: understanding the role of policy, race & real estate in Cuyahoga County. Retrieved from http://kirwaninstitute.osu.edu/wp-content/uploads/2015/06/The-History-of-Race-Real-Estate-Cuyahoga-County-Final-Report-February-2015.pdf
p. 30: The Child Opportunity Index (COI) 2.0 is one approach to quantifying the enormous variation in resources and conditions available for healthy living in the United States. Acevedo-Garcia, D., McArdle, N., Hardy, E. F., Crisan, U. I., Romano, B., Norris, D., … Reece, J. (2014). The child opportunity index: improving collaboration between community development and public health. Health Affairs, 33(11), 1948–1957 ; and 25367989 Noelke, C., McArdle, N., Baek, M., Huntington, N., Huber, R., Hardy, E., & Acevedo-Garcia, D. (2020). Child Opportunity Index 2.0 technical documentation. Retrieved from http://diversitydatakids.org/sites/default/files/2020-01/ddk_coi2.0_technical_documentation_20200115_1.pdf
p. 31: Figure 2.1. Source: Calculations are based on data from COI 2.0: diversitydatakids.org. (n.d.). Child Opportunity Index 2.0, 2019. Waltham, MA: Brandeis University, The Heller School for Social Policy and Management, Institute for Child Youth and Family Policy.
p. 32: Figure 2.2. Sources: Child Opportunity Index 2.0, 2019: diversitydatakids.org. (n.d.). Child Opportunity Index 2.0, 2019. Waltham, MA: Brandeis University, The Heller School for Social Policy and Management, Institute for Child Youth and Family Policy ; and Life expectancy data from the U.S. Small-Area Life Expectancy Estimates Project (CDC-NCHS).
p. 32: Figure 2.3. Source: Centers for Disease Control and Prevention. (2020). Life expectancy at birth for U.S. Census tracts, 2010–2015. Retrieved from https://www.cdc.gov/surveillance/blogs-stories/life-expectancy.html
p. 33: Percentages of children, by race/ethnicity, who live in neighborhoods across the various levels of opportunity. diversitydatakids.org. (n.d.). Child Opportunity Index 2.0, 2019. Waltham, MA: Brandeis University, The Heller School for Social Policy and Management, Institute for Child Youth and Family Policy.
p. 33: Disparities in educational achievement are linked directly to levels of child neighborhood opportunity. Harding, D. J. (2003). Counterfactual models of neighborhood effects: The effect of neighborhood poverty on dropping out and teenage pregnancy. American Journal of Sociology, 109(3), 676–719.
p. 33: Income distribution attained as adults compared with income distribution that their parents attained. Chetty, R., Friedman, J. N., Hendren, N., Jones, M. R., & Porter, S. R. (2018). The Opportunity Atlas: Mapping the childhood roots of social mobility. Retrieved from https://ideas.repec.org/p/cen/wpaper/18-42.html
p. 33: Proportion of children earning more than their parents. Chetty, R., Grusky, D., Hell, M., Hendren, N., Manduca, R., & Narang, J. (2016). The fading American dream: Trends in absolute income mobility since 1940. Retrieved from http://www.nber.org/papers/w22910
p. 34: Figure 2.4. Sources: Calculated based on data from COI 2.0: diversitydatakids.org. (n.d.). Child Opportunity Index 2.0, 2019. Waltham, MA: Brandeis University, The Heller School for Social Policy and Management, Institute for Child Youth and Family Policy. Population data from the American Community Survey, 5-Year Summary Files. Average household income at 35 years of age from Chetty, R., Friedman, J. N., Hendren, N., Jones, M. R., & Porter, S. R. (2018). The Opportunity Atlas: Mapping the childhood roots of social mobility. Retrieved from https://ideas.repec.org/p/cen/wpaper/18-42.html

## Chapter 3 The Meaning, Purpose, and Opportunity of Business in 21st Century America

p. 41: Introductory quote. Smith, A. (1776). The wealth of nations. Oxford, England: Bibliomania.com Ltd. Retrieved from https://www.loc.gov/item/2002564559/
p. 42: “Shareholder primacy.” Business Roundtable. (2019, August 19). Business Roundtable redefines the purpose of a corporation to promote “an economy that serves all Americans”. Retrieved from https://www.businessroundtable.org/business-roundtable-redefines-the-purpose-of-a-corporation-to-promote-an-economy-that-serves-all-americans ; Ireland, P. (2005). Shareholder primacy and the distribution of wealth. The Modern Law Review, 68(1), 49–81 ; and Rock, E. B. (2013). Adapting to the new shareholder-centric reality (Faculty Scholarship Paper 457). Retrieved from http://scholarship.law.upenn.edu/faculty_scholarship/457
p. 42: Income inequality increased as real incomes for employees stagnated. Owyang, M. T., & Shell, H. G. (2016, March 30). Measuring trends in income inequality. Retrieved from https://www.stlouisfed.org/publications/regional-economist/april-2016/measuring-trends-in-income-inequality ; and Piketty, T., & Saez, E. (2003). Income inequality in the United States, 1913–1998. Quarterly Journal of Economics, 118(1), 1–39.
p. 42: Government regulation or deregulation facilitated some trends around income inequality and real income. Beck, T., Levine, R., & Levkov, A. (2010). Big bad banks? The winners and losers from bank deregulation in the United States. The Journal of Finance, 65(5), 1637–1667 ; and Bergh, A., & Nilsson, T. (2010). Do liberalization and globalization increase income inequality? European Journal of Political Economy, 26(4), 488–505.
p. 42: Role of three systemic changes on the rise in wage inequality. Fortin, N. M., & Lemieux, T. (1997). Institutional changes and rising wage inequality: Is there a linkage? Journal of Economic Perspectives, 11(2), 75–96.
p. 42: The widening gap in pay between company leaders and managers and lower level workers. Mishel, L., & Wolfe, J. (2019, August 14). CEO compensation has grown 940% since 1978: Typical worker compensation has risen only 12% during that time. Retrieved from https://www.epi.org/publication/ceo-compensation-2018/
p. 42: Quote from Milton Friedman. As cited in Friedman, M. (1970, September 13). The social responsibility of business is to increase its profits. Retrieved from http://umich.edu/~thecore/doc/Friedman.pdf
p. 43: “Reversal of fortune.” Case, A., & Deaton, A. (2015). Rising morbidity and mortality in midlife among White non-Hispanic Americans in the 21st century. Proceedings of the National Academy of Sciences, 112(49), 15078–15083 ; and Paez, K. (2015, December 1). Rising death rates bring new meaning to mid-life crisis for Americans—especially White women. Retrieved from https://www.air.org/resource/rising-death-rates-bring-new-meaning-mid-life-crisis-americans-especially-white-women
p. 43: Many businesses have begun to reevaluate their role in society and see opportunities in becoming partners in creating healthy, inclusive, and prosperous communities. Enright, S., McElrath, R., & Taylor, A. (2016, October). The future of stakeholder engagement: Transformative engagement for inclusive business. Retrieved from https://www.bsr.org/reports/BSR_Future_of_Stakeholder_Engagement_Report.pdf
p. 43: Mutualism between businesses and the communities in which they operate. Birchall, J. (2002). The new mutualism in public policy. London, UK: Routledge ; Frederick, W. C. (1998). Creatures, corporations, communities, chaos, complexity: A naturological view of the corporate social role. Business & Society, 37(4), 358–389 ; Hills, G., & Hawkins, E. (n.d.). Advancing strategy: How to lead change in corporate societal engagement. Retrieved from https://www.fsg.org/tools-and-resources/advancing-strategy ; and Porter, M. E., & Kramer, M. R. (2011). Creating shared value. Harvard Business Review, 89, 62–77.
p. 44: Figure 3.1. Source: Adapted with permission from Pew Research Center, as appearing on page 19 of Horowitz, J. M., Igielnik, R., & Kochhar, R. (2020, January 9). Most Americans say there is too much economic inequality in the U.S., but fewer than half call it a top priority. Retrieved from https://www.pewsocialtrends.org/2020/01/09/most-americans-say-there-is-too-much-economic-inequality-in-the-u-s-but-fewer-than-half-call-it-a-top-priority/
p. 44: Quote from Larry Fink. Fink, L. (2019). Larry Fink’s 2019 letter to CEOs: Profit & purpose. Retrieved from https://www.blackrock.com/americas-offshore/2019-larry-fink-ceo-letter
p. 45: A majority of U.S. adults is dissatisfied with the size and influence of major corporations. Riffkin, R. (2016, January 20). Majority of Americans dissatisfied with corporate influence. Retrieved from https://news.gallup.com/poll/188747/majority-americans-dissatisfied-corporate-influence.aspx
p. 45: Americans have “a great deal” or “quite a lot” of confidence in small businesses. Newport, F. (2017, August 22). Business gets bigger even as Americans prefer small. Retrieved from https://news.gallup.com/opinion/polling-matters/216674/business-gets-bigger-even-americans-prefer-small.aspx
p. 45: Differences in U.S. opinion are driven by perspectives about leaders of large corporations. Riffkin, R., & Wilson, G. (2016, January 21). Large and growing majority of Americans dissatisfied with corporate influence. Retrieved from https://www.newamericanjournal.net/2016/01/large-and-growing-majority-of-americans-dissatisfied-with-corporate-influence/
p. 45: Unencumbered markets and government policies that favor business are linked to inequality and lack of economic opportunity. Putnam, R. D. (2015). Our kids: The American dream in crisis. New York, NY: Simon & Schuster.
pp. 45–46: Strong, pro-market leaders. Cramer, A (2019, October 25). Capitalism is not working. Here’s how business leaders can fix it. Retrieved from https://qz.com/work/1728603/how-business-leaders-can-fix-capitalism/
p. 46: The sustainability of capitalism is questionable if a more equitable distribution of benefits cannot be implemented. Piketty, T. (2014). Capital in the twenty-first century. Cambridge, MA: The Belknap Press of Harvard University Press.
p. 46: The perception (if not the reality) of capitalism in crisis. Milanovic, B. (2019). Capitalism, alone: The future of the system that rules the world. Cambridge, MA: The Belknap Press of Harvard University Press.
p. 46: Part of the core of American identity is based on economic opportunity. Lipset, S. M., & Bendix, R. (2018). Social mobility in industrial society. Oakland, CA: University of California Press.
p. 46: American dream. Chetty, R. (2016). Socioeconomic mobility in the United States: New evidence and policy lessons. In S. M. Wachter & L. Ding (Eds.), Shared prosperity in America’s communities (pp. 7–19). Philadelphia, PA: University of Pennsylvania Press ; Chetty, R., Friedman, J. N., Hendren, N., Jones, M. R., & Porter, S. R. (2018). The Opportunity Atlas: Mapping the childhood roots of social mobility. Retrieved from https://ideas.repec.org/p/cen/wpaper/18-42.html ; Chetty, R., Grusky, D., Hell, M., Hendren, N., Manduca, R., & Narang, J. (2017). The fading American dream: Trends in absolute income mobility since 1940. Science, 356(6336), 398–406 ; and 28438988 Hout, M. (2015). A summary of what we know about social mobility. The ANNALS of the American Academy of Political and Social Science, 657(1), 27–36.
p. 46: Economic advancement remains stronger in other wealthy nations than in the United States. Causa, O., & Johansson, A. (2010). Intergenerational social mobility in OECD countries. Retrieved from http://www.oecd.org/social/labour/49849281.pdf ; and Gould, E. (2012, October 10). U.S. lags behind peer countries in mobility. Retrieved from https://www.epi.org/publication/usa-lags-peer-countries-mobility/
pp. 47: Increasing interdependence and mutuality between business and society. Stephenson, C. (2008). Creating shared value: The inseparability of business and society. Retrieved from https://iveybusinessjournal.com/publication/creating-shared-value-the-inseparability-of-business-and-society/
p. 47: Increasing interest in the values vetting of equity markets. US SIF. (2018). Sustainable and impact investing—overview. Retrieved from https://www.ussif.org/files/2018%20Infographic%20overview%20(1).pdf
pp. 48: Strategic Management: A Stakeholder Approach. Freeman, R. E. (2010). Strategic management: A stakeholder approach. Cambridge, UK: Cambridge University Press.
p. 48: “Constituency” laws. Flammer, C., & Kacperczyk, A. (2016). The impact of stakeholder orientation on innovation: Evidence from a natural experiment. Management Science, 62(7), 1982–2001 ; and Stout, L. (2012). The shareholder value myth: How putting shareholders first harms investors, corporations, and the public. San Francisco, CA: Berrett-Koehler Publishers.
p. 49: Firms that consistently implement a stakeholder approach tend to achieve better outcomes. Choi, J., & Wang, H. (2009). Stakeholder relations and the persistence of corporate financial performance. Strategic Management Journal 30(8), 895–907 ; De Bussy, N. M., & Suprawan, L. (2012). Most valuable stakeholders: The impact of employee orientation on corporate financial performance. Public Relations Review, 38(2), 280–287 ; Dizik, A. (2016, February 21). The relationship between corporate culture and performance: Researchers find that a positive culture boosts performance, but performance alone doesn’t create a positive culture. Retrieved from https://www.wsj.com/articles/the-relationship-between-corporate-culture-and-performance-1456110320 ; Edmans, A. (2011). Does the stock market fully value intangibles? Employee satisfaction and equity prices. Journal of Financial Economics, 101(3), 621–640 ; Edmans, A. (2016, March 24). 28 years of stock market data shows a link between employee satisfaction and long-term value. Retrieved from https://hbr.org/2016/03/28-years-of-stock-market-data-shows-a-link-between-employee-satisfaction-and-long-term-value ; Graves, S. B., & Waddock, S. A. (2000). Beyond built to last …: Stakeholder relations in built-to-last companies. Business and Society Review, 105(4), 393–418 ; Kestenbaum, R. (2018, December 4). Customer satisfaction is more important than you thought. Retrieved from https://www.forbes.com/sites/richardkestenbaum/2018/12/04/customer-satisfaction-is-more-important-than-you-thought/#76d58fc55ed9 ; Laughland, P. (2011, June 10). Stakeholder relations sustain positive financial performance. Retrieved from https://www.nbs.net/articles/stakeholder-relations-sustain-positive-financial-performance ; and Shaheen, I., & Naseem, N. (2015). A review of customer satisfaction, employee satisfaction and their impact on firm performance. International Journal of Management & Organizational Studies 4(1), 34–38.
p. 49: Quote from Tony Schwarz: Schwartz, T. (2013, April 4). Companies that practice “conscious capitalism” perform 10x better. Retrieved from https://hbr.org/2013/04/companies-that-practice-conscious-capitalism-perform
p. 49: Positive reciprocity can create a virtuous cycle of benefits for business and society. Bosse, D. A., Phillips, R. A., & Harrison, J. S. (2008). Stakeholders, reciprocity, and firm performance. Strategic Management Journal, 30(4), 447–456.
p. 50: Footnote. Applications of stakeholder theory: Scholl, H. J. (2001). Applying stakeholder theory to e-government. In B. Schmid, K. Stanoevska-Slabeva, & V. Tschammer (Eds.), Towards the e-society: E-commerce, e-business, and e-government (pp. 735–747). Boston, MA: Springer.
p. 50: Business Roundtable’s revised statement on the purpose of a corporation. Business Roundtable. (2019, August 19). Business Roundtable redefines the purpose of a corporation to promote “an economy that serves all Americans”. Retrieved from https://www.businessroundtable.org/business-roundtable-redefines-the-purpose-of-a-corporation-to-promote-an-economy-that-serves-all-americans
p. 51: Box 3.2. Source: N. Abebe, Sodexo, personal communication, February 20, 2020.
p. 52: Stakeholders and businesses are interdependent and linked together in a larger ecosystem. Coalition for Inclusive Capitalism. (2018, December). EPIC: Embankment Project for Inclusive Capitalism. Retrieved from https://www.epic-value.com/ ; and Fink, L. (n.d.). A fundamental reshaping of finance. Retrieved from https://www.blackrock.com/corporate/investor-relations/larry-fink-ceo-letter

## Chapter 4 Bringing Opportunity to Communities Through Partnerships With Community Development and Community Finance

p. 63: Community development organizations specialize in real estate, city planning, law, social work, public policy, public health, affordable housing, and finance. Build Healthy Places Network. (n.d.). Jargon buster: Community development. Retrieved from https://www.buildhealthyplaces.org/jargon-buster
p. 63: Box 4.1. “A program for housing, without simultaneous programs for jobs, education, welfare reform, health, and economic development cannot succeed”: Page 806 in Newfield, J. (2002). Bedford-Stuyvesant: Giving a damn about hell, from “Robert Kennedy: A Memoir”. In K. T. Jackson & D. S. Dunbar (Eds.), Empire City: New York through the centuries (pp. 798–807). New York, NY: Columbia University Press. New nonprofit entities dedicated to antipoverty work: Erickson, D. (2009). The housing policy revolution: Networks and neighborhoods. Washington, DC: Urban Institute ; and Erickson, D., & Andrews, N. (2011). Partnerships among community development, public health, and health care could improve the well-being of low-income people. Health Affairs, 30(11), 2056–2063.22068396
p. 64: Community development corporations (CDCs) as nonprofit organizations. National Alliance of Community Economic Development Associations. (n.d.). What is community development. Retrieved from https://www.naceda.org/what-we-do
p. 64: Approximately 4,600 CDCs exist in the United States. Erekaini, R. (2014). What is a community development corporation: A brief explanation of the community development field. Retrieved from https://www.naceda.org/index.php?option=com_dailyplanetblog&view=entry&category=bright-ideas&id=25%3Awhat-is-a-community-development-corporation-&Itemid=171
p. 64: East Bay Asian Local Development Corporation (EBALDC). East Bay Asian Local Development Corporation. (n.d.). The Healthy Havenscourt Collaborative. Retrieved from https://ebaldc.org/what-we-do/neighborhood-collaborations/the-healthy-havenscourt-collaborative/
p. 64: Stewards of Affordable Housing for the Future (SAHF) is a national network of the 13 largest nonprofit affordable-housing developers. Stewards of Affordable Housing for the Future. (n.d.). Our story: About SAHF. Retrieved from http://www.sahfnet.org/our-story
p. 65: Net charge-off rate among CDFIs in 2017. Opportunity Finance Network. (n.d.). About OFN. Retrieved from https://ofn.org/OFN
p. 65: Box 4.2. As quoted in CDFI Fund. (n.d.). CDFI certification. Retrieved from https://www.cdfifund.gov/programs-training/certification/cdfi/Pages/default.aspx
p. 65: Figure 4.1. Source: Adapted with permission from CDFI Fund. (2019). A year of investment ’18 (Annual Report). Retrieved from https://www.cdfifund.gov/Documents/CDFITO2_YIR18_Final508_20190321.pdf
p. 66: Many CDCs are “rooted in and [root] for struggling communities.” Page 34 in Erickson, D. (2017). The march towards outcomes-based funding. In Federal Reserve Bank of San Francisco & Nonprofit Finance Fund (Eds.), What matters: Investing in results to build strong, vibrant communities (pp. 29–55). San Francisco, CA: Federal Reserve Bank of San Francisco.
pp. 66–67: Building Healthy Communities. As quoted in The California Endowment. (n.d.). Our focus areas. Retrieved from https://www.calendow.org/focus-area-list/
p. 67: Movement across the field emphasizes the longer term need to build relationships and support the lasting power in the community as a means of transformative change. Choi, L. (2019). Testing our hypotheses on equitable development: Midcourse learning and adapting through SPARCC (Community Development Research Brief). San Francisco, CA: Federal Reserve Bank of San Francisco.
p. 67: 11.8% of Americans lived below the federal poverty line in 2018. Semega, J., Kollar, M., Creamer, J., & Mohanty, A. (2019, September). Income and poverty in the United States: 2018 (Current Population Reports, No. P60-266). Washington, DC: U.S. Government Printing Office. Retrieved from https://www.census.gov/content/dam/Census/library/publications/2019/demo/p60-266.pdf
p. 67: About 6% of Americans lived in counties characterized by persistent poverty. Housing Assistance Council. (n.d.). Persistent poverty. Retrieved from http://www.ruralhome.org/sct-initiatives/mn-persistent-poverty
p. 67: Median household income and net worth. Amadeo, K. (2019, April 22). What is the average American net worth? Compare your wealth to that of the average American. Retrieved at https://www.thebalance.com/american-net-worth-by-state-metropolitan-4135839 ; and Guzman, G. (2019, September 26). New data show income increased in 14 states and 10 of the largest metros. Retrieved from https://www.census.gov/library/stories/2019/09/us-median-household-income-up-in-2018-from-2017.html
p. 67: Link between economic distress and poorer health. Healthypeople.gov. (n.d.). Poverty. Retrieved from https://www.healthypeople.gov/2020/topics-objectives/topic/social-determinants-health/interventions-resources/poverty
p. 68: Figure 4.2. Source: Adapted from CDFI Fund. (2015, August 20). Financial resources for CDFI expansion. Retrieved from https://www.cdfifund.gov/Documents/6-Financial%20Resources%20for%20CDFI%20Expansion.pdf and from personal communication with Annie Donovan, MBA, Local Initiatives Support Corporation (LISC).
p. 68: Figure 4.3. Source: CDFI Fund. (2019). A year of investment ’18 (Annual Report). Retrieved from https://www.cdfifund.gov/Documents/CDFITO2_YIR18_Final508_20190321.pdf
p. 69: Assets of CDFIs. CDFI Fund. (2019). A year of investment ’18 (Annual Report). Retrieved from https://www.cdfifund.gov/Documents/CDFITO2_YIR18_Final508_20190321.pdf
p. 70: Footnote. Figures on CDFI Fund activities are based on CDFI Fund’s 2018 annual report: CDFI Fund. (2019). A year of investment ’18 (Annual Report). Retrieved from https://www.cdfifund.gov/Documents/CDFITO2_YIR18_Final508_20190321.pdf. Figures on CDFI Fund activities are also based on financial audits for fiscal years 2017 and 2018 using internal data from Office of Inspector General. (2018, November 14). Audit of the Community Development Financial Institution Fund’s financial statements for fiscal years 2018 and 2017 (OIG-19-014). Washington, DC: U.S. Department of the Treasury. Retrieved from https://www.treasury.gov/about/organizational-structure/ig/Audit%20Reports%20and%20Testimonies/OIG-19-014.pdf
pp. 69–70: Healthy Food Financing Initiative (HFFI). Policy Link, The Food Trust, & The Reinvestment Fund. (2015, April 14). The Healthy Food Financing Initiative (HFFI): An innovative public-private partnership sparking economic development and improving health. Retrieved from https://www.frbsf.org/community-development/files/healthy_food_financing_initiative.pdf
p. 70: Most programs attract about $8 of private capital for every $1 of federal spending. CDFI Fund. (2019). A year of investment ’18 (Annual Report). Retrieved from https://www.cdfifund.gov/Documents/CDFITO2_YIR18_Final508_20190321.pdf
p. 70: Award recipients reported originating loans or investments in FY 2018 totaling over $11 billion. Page 3 in Donovan, A. (2019, February 6). Written testimony of Annie Donovan, senior fellow, Center for Community Investment, before the House Appropriations Committee on Financial Services and General Government on the Community Development Financial Institutions Fund at the U.S. Department of the Treasury. Retrieved from https://docs.house.gov/meetings/AP/AP23/20190226/108952/HHRG-116-AP23-Wstate-DonovanA-20190226.pdf
p. 70: Products and services delivered to underserved people and communities contribute to the strengthening of individuals, families, and communities and to health, wealth, and well-being. CDFI Fund. (2019). A year of investment ’18 (Annual Report). Retrieved from https://www.cdfifund.gov/Documents/CDFITO2_YIR18_Final508_20190321.pdf
pp. 70–71: Additional support can have a lasting impact on quality of life and community health outcomes. CDFI Fund. (2019). A year of investment ’18 (Annual Report). Retrieved from https://www.cdfifund.gov/Documents/CDFITO2_YIR18_Final508_20190321.pdf
p. 71: Box 4.3. Source: Page 4 in Donovan, A. (2019, February 6). Written testimony of Annie Donovan, senior fellow, Center for Community Investment, before the House Appropriations Committee on Financial Services and General Government on the Community Development Financial Institutions Fund at the U.S. Department of the Treasury, p. 4. Retrieved from https://docs.house.gov/meetings/AP/AP23/20190226/108952/HHRG-116-AP23-Wstate-DonovanA-20190226.pdf. Areas of persistent poverty: Gonzales, O. (2016, June 1). Snap stat: Sizing up certified CDFIs [CDFI Fund Impact blog]. Retrieved from https://www.cdfifund.gov/Documents/Snap%20Stat%20June%201,%202016.pdf
pp. 71–72: Loss rates of CDFI loans. Opportunity Finance Network. (2017, January 31). 20 years of CDFI banks and credit unions 1996–2015: An analysis of trends and growth. Retrieved from https://ofn-drupal-pub.s3.amazonaws.com/s3fs-public/OFN_CDFI_CreditUnion_LongStudy_FINAL.pdf
p. 72: Operational efficiency and risk level of CDFIs compared with mainstream banks. Fairchild, G. B., & Jia, R. (2014, August). Risk and efficiency among CDFIs: A statistical evaluation using multiple models. Washington, DC: U.S. Department of the Treasury. Retrieved from https://www.cdfifund.gov/Documents/Risk%20and%20Efficiency%20among%20CDFIs%20Report.pdf
p. 72: Actions by businesses that want to contribute to community investments. Mattiuzzi, E. (2019). Funds for kickstarting affordable housing preservation and production: Lessons for new investors. Retrieved from https://www.frbsf.org/community-development/files/funds-for-kickstarting-affordable-housing-preservation-and-production-lessons-for-new-investors.pdf
pp. 73–74: Loans from CRA-motivated banks. Goodman, L., Zhu, J., & Walsh, J. (2020). The Community Reinvestment Act: What do we know, and what do we need to know? Housing Policy Debate, 30(1), 83–100.
p. 74: Through the LIHTC program, states receive an annual allocation of federal tax credits based on size of population. Gramlich, E. (2018). Low income housing tax credits Advocates guide 2018: A primer on federal affordable housing & community development programs (pp. 5-30–5-37). Washington, DC: National Low Income Housing Coalition. Retrieved from http://nlihc.org/sites/default/files/AG-2018/Ch05-S09_LIHTC_2018.pdf
p. 74: LIHTC financing and support. National Multifamily Housing Council. (2019). Low income housing tax credit (LIHTC). Retrieved from https://www.nmhc.org/contentassets/dd59ef1e61da4b6fb0a10c573fb4176a/lihtc_fact_sheet_2019_2.pdf
p. 74: Funding, jobs, and other support from NMTC. CDFI Fund. (n.d.). New Markets Tax Credit Program: Community revitalization by rewarding private investment. Retrieved from https://www.cdfifund.gov/Documents/NMTC%20Fact%20Sheet_Jan2018.pdf ; and CDFI Fund. (n.d.). NMTC Program award book CY 2018. Retrieved from https://www.cdfifund.gov/Documents/New%20Markets%20Tax%20Credit%20Program%20Award%20Book%20for%20Calendar%20Year%202018.pdf
p. 74: California’s Affordable Housing and Sustainable Communities Program. Affordable Housing and Sustainable Communities Program. (2019). Affordable Housing and Sustainable Communities Program: FY 2017–2018 recommended awards (Agenda Item #6). Retrieved from http://sgc.ca.gov/meetings/council/2019/docs/20190621-Item6_AHSC_R4_Awards_StaffReport.pdf
p. 75: Health systems have invested directly in community development efforts. Duffrin, L. (2017, July 20). Building on tradition, Catholic hospitals invest in community to improve health. Retrieved from https://medium.com/bhpn-crosswalk/building-on-tradition-catholic-hospitals-invest-in-community-to-improve-health-2b0d9238edd1 ; HUD User. (2018). ProMedica focuses on community development to strengthen health in Toledo, Ohio. Retrieved from https://www.huduser.gov/portal/casestudies/study-060418.html ; HUD User. (n.d.). UnitedHealthcare helps a nonprofit in Phoenix provide Medicaid members with housing and services. Retrieved from https://www.huduser.gov/portal/casestudies/study-071818.html ; Kaiser Permanente. (2018). Studies show decade-long community health efforts are promising. Retrieved from https://about.kaiserpermanente.org/community-health/news/kaiser-permanente-releases-results-of-decade-long-community-heal ; and Ray, B. (2017, February 23). A new responsibility for children’s hospitals: The health of neighborhoods. Retrieved from https://medium.com/bhpn-crosswalk/a-new-responsibility-for-childrens-hospitals-the-health-of-neighborhoods-257107d6051f
p. 75: Communities enriched with the vital conditions for health, wealth, and well-being are economically resilient. Committee on Post-Disaster Recovery of a Community’s Public Health, Medical, and Social Services; Board on Health Sciences Policy; & Institute of Medicine. (2015). Healthy, resilient, and sustainable communities after disasters: Strategies, opportunities, and planning for recovery. Washington, DC: National Academies Press.
p. 76: Expanding skills and assets at the “person level.” Choi, L., Erickson, D., Griffin, K., Levere, A., & Seidman, E. (Eds.). (2015). What it’s worth: Strengthening the financial future of families, communities, and the nation. San Francisco, CA: Federal Reserve Bank of San Francisco and Corporation for Enterprise Development.
p. 76: Savings accounts for children who live in families with low- and moderate-level incomes. Elliott, W., Song, H., & Nam, I. (2013). Small-dollar children’s savings accounts, income, and college outcomes (Center for Social Development Publication No. 13-06). St. Louis, MO: Washington University.
p. 76: Outcomes of members of FOCs. Roder, A. (2016). First steps on the road to financial well-being: Final report from the evaluation of LISC’s Financial Opportunity Centers. Retrieved from http://www.lisc.org/media/filer_public/f7/f7/f7f7402d-690d-47f5-a7fa-537ab7b793c4/16024-first-steps_r5-report-web.pdf
pp. 76–77: A growing movement toward “outcomes-based financing.” Page 472 in Bugg-Levine, A. (2017). From funding activities to investing in results: How do we get from here to there? In Federal Reserve Bank & San Francisco and Nonprofit Finance Fund (Eds.), What matters: Investing in results to build strong, vibrant communities (pp. 472–479). San Francisco, CA: Federal Reserve Bank of San Francisco and Nonprofit Finance Fund.
p. 77: Nimble and patient financing. Page 4 in Mattiuzzi, E. (2019). Funds for kickstarting affordable housing preservation and production: Lessons for new investors. Retrieved from https://www.frbsf.org/community-development/files/funds-for-kickstarting-affordable-housing-preservation-and-production-lessons-for-new-investors.pdf
p. 78: Box 4.4. The HFF supports financing of community health centers and affordable housing in underserved areas: Local Initiatives Support Corporation. (n.d.). Financial opportunity center. Retrieved from https://www.lisc.org/our-initiatives/financial-stability/financial-opportunity-centers/. So Others Might Eat: So Others Might Eat. (n.d.). About Affordable Housing Initiative. Retrieved from https://www.some.org/about/affordable-housing-initiative. Denver Regional Transit-Oriented Development Fund: Enterprise. (2018). Denver Regional Transit-Oriented Development (TOD) Fund. Retrieved from https://www.enterprisecommunity.org/financing-and-development/community-loan-fund/denver-regional-tod-fund
p. 78: Box 4.5. Survey of employers in the Greater Boston area: Northeastern University School of Public Policy & Urban Affairs. (2017). Assessing affordable housing availability and its effects on employers’ ability to recruit and retain employees in Greater Boston. Retrieved from https://www.mhp.net/writable/resources/documents/MHP-Report-Final_042817.pdf. Survey of employers regarding jobs in Los Angeles: Los Angeles Business Council. (2017, March). The affordable housing crisis in Los Angeles: A business perspective. Retrieved from https://labusinesscouncil.org/wp-content/uploads/2019/04/The-Affordable-Housing-Crisis-in-Los-Angeles-An-Employer-Perspective.pdf
p. 79: Improvements raise the risk of gentrification. Urban Displacement Project. (n.d.). Gentrification explained. Retrieved from https://www.urbandisplacement.org/gentrification-explained
p. 79: “606” recreational trail in Chicago. Smith, G., Duda, S., Man Lee, J., & Thompson, M. (2016). Measuring the impact of the 606: Understanding how a large public investment impacted the surrounding housing market. Retrieved from https://www.housingstudies.org/media/filer_public/2016/10/31/ihs_measuring_the_impact_of_the_606.pdf
p. 79: Responses to pressures from the housing market. Linares, J. C. (2017). Panel recap: The impact of infrastructure on communities. Retrieved from https://greatcities.uic.edu/2017/10/04/panel-recap-the-impact-of-infrastructure/
p. 79: The availability of affordable housing is critical to preventing displacement. Aboelata, M. J., Bennett, R., Yañez, E., Bonilla, A., & Akhavan, N. (2017). Healthy development without displacement: Realizing the vision of Healthy Communities for All. Oakland, CA: Prevention Institute.
p. 80: Preventing gentrification and displacement. Nathalie P. Voorhees Center for Neighborhood and Community Improvement. (2015). Gentrification and neighborhood change: Helpful tools for communities—A supplement to the socioeconomic change of Chicago’s community areas (1970–2010). Retrieved from http://voorheescenter.red.uic.edu/wp-content/uploads/sites/122/2017/10/Gentrification-and-Neighborhood-Change-Toolkit.pdf
p. 80: Challenges ahead require a new business model that more closely aligns the financial interests of those who stand to benefit from a healthier, more productive population with the capacities of those who create the conditions that promote human flourishing. Erickson, D. (2017). The march towards outcomes-based funding. In Federal Reserve Bank of San Francisco & Nonprofit Finance Fund (Eds.), What matters: Investing in results to build strong, vibrant communities (pp. 29–55). San Francisco, CA: Federal Reserve Bank of San Francisco.

## Chapter 5 Working With Community Changemakers

p. 88: An array of enterprises, including social enterprises, provide investments and services that make people and communities healthy, vibrant, strong, and resilient. Dart, R. (2004). The legitimacy of social enterprise. Nonprofit Management & Leadership, 14(4), 411–424 ; and Social Enterprise Alliance. (n.d.). What is social enterprise? Retrieved from https://socialenterprise.us/about/social-enterprise/
p. 88: Social enterprises are hybrids of sort. Santos, F. M., Pache, A.-C., & Birkholz, C. (2015). Making hybrids work: Aligning business models and organizational design for social enterprises. California Management Review, 57(3), 36–58 ; and Wry, T., & York, J. G. (2017). An identity-based approach to social enterprise. Academy of Management Review, 42(3), 437–460.
p. 88: The term “impact investing.” Bugg-Levine, A., & Emerson, J. (2011, September). Impact investing: Transforming how we make money while making a difference. San Francisco, CA: Jossey-Bass ; and Global Impact Investment Network. (n.d.). Impact investing. Retrieved from https://thegiin.org/impact-investing/
p. 90: Cost to evict a family, and cost to prevent eviction. HomeStart. (n.d.). Eviction prevention. Retrieved from https://www.homestart.org/prevention
pp. 90–91: Details around the expanded operations of First Step Staffing. Impact PHL. (n.d.). Local capital collaboration brings First Step Staffing to Philadelphia. Retrieved from https://uploads-ssl.webflow.com/5dfd361710bfa7d68d8da821/5e7b9e48c4f3f038b2b6c2da_Impact-PHL_Investment-Case-Study_First-Step-Staffing_April-2019.pdf
p. 91: Business can invest in First Step Staffing through debt and philanthropic equity. First Step Staffing. (2018, January 10). Atlanta-based First Step staffing expands into Philadelphia; acquires portion of On Time Staffing to form unique job training & placement for homeless and returning citizens. Retrieved from https://firststepstaffing.com/blog/atlanta-based-first-step-staffing-expands-into-philadelphia-acquires-portion-of-on-time-staffing-to-form-unique-job-training-placement-for-homeless-and-returning-citizens/
p. 92: Asset-based approach to successful collaborations. Leavitt, M. O., & McKeown, R. (2013). Finding allies, building alliances: 8 elements that bring—and keep people together. San Francisco, CA: Jossey-Bass.
p. 93: Community preventive services. The Community Guide. (n.d.). [Home page]. Retrieved from https://www.thecommunityguide.org/
p. 93: Clinical preventive services. U.S. Preventive Services Task Force. (2014). The guide to clinical preventive services. Washington, DC: Agency for Healthcare Research and Quality. Retrieved from https://www.ahrq.gov/sites/default/files/publications/files/cpsguide.pdf
p. 93: One of the roles of a public health department in the 21st century is to be the chief health strategist of a community. DeSalvo, K. B., Wang, Y. C., Harris, A., Auerbach, J., Koo, D., & O’Carroll, P. (2017). Public health 3.0: A call to action for public health to meet the challenges of the 21st century. Preventing Chronic Disease, 14, E78 ; and 28880837 RESOLVE. (2014). The high achieving governmental health department in 2020 as the community chief health strategist. Retrieved from https://www.resolve.ngo/docs/the-high-achieving-governmental-health-department-as-the-chief-health-strategist-by-2020-final1636869407709140046.pdf
p. 94: Figure 5.1. Source: Adapted with permission from Prison Policy Initiative: Wagner, P., & Sawyer, W. (2018, June). States of incarceration: The global context 2018. Retrieved from https://www.prisonpolicy.org/global/2018.html
p. 95: Incarceration negatively affects the broader labor market. Immerman, D. (2017). The economic impact of incarceration: Measuring and exploring incarceration-related costs across the United States (Economic Student Theses and Capstone Projects, 54, Skidmore College). Retrieved from https://pdfs.semanticscholar.org/c287/af2530f92fd64eefac427a6f5dc7ec242524.pdf
p. 95: Incarceration creates barriers to current and future employment. Pager, D. (2003). The mark of a criminal record. American Journal of Sociology, 108(5), 937–975.
p. 95: Incarceration is associated with high rates of death from drug overdose, lower median household incomes, and poor health outcomes. Nosrati, E., Kang-Brown, J., Ash, M., McKee, M., Marmot, M., & King, L. P. (2019). Economic decline, incarceration, and mortality from drug use disorders in the USA between 1983 and 2014: An observational analysis. The Lancet Public Health, 4(7), e326–e333.31279417
p. 95: Incarceration has long-term implications for families and children. Subramanian, R., Delaney, R., Roberts, S., Fishman, N., & McGarry, P. (2015, updated February 29). Incarceration’s front door: The misuse of jails in America. New York, NY: Vera Institute of Justice. Retrieved from https://www.vera.org/downloads/publications/incarcerations-front-door-report_02.pdf
p. 95: Children of incarcerated parents are six times more likely to become incarcerated themselves. Martin, E. (2017). Hidden consequences: The impact of incarceration on dependent children. In NIJ Journal, 278. Retrieved from https://www.ncjrs.gov/pdffiles1/nij/250349.pdf
p. 95: Quote from H. E. “Gene” Rainbolt. Schulte, B. (2019, October 31). Oklahoma focuses on criminal justice reform. Retrieved from https://www.usnews.com/news/best-states/articles/2019-10-31/oklahoma-focuses-on-criminal-justice-reform
p. 95: Findings from an analysis by the Vera Institute of Justice regarding jails in Oklahoma County. Fishman, N., Kall, K., Silber, R., LaChance, J., Dershowitz, H., & Roberts, S. (2016, December). Greater Oklahoma City Chamber Criminal Justice Reform Task Force: Report and recommendations. New York, NY: Vera Institute of Justice. Retrieved from https://www.vera.org/downloads/publications/OK-chamber-final-report.pdf
p. 96: Justice system reform in Oklahoma City and County stemming from the work of community stakeholders. Butcher, K. (2017, September 9). Oklahoma County jail population falls below 2,000 inmates, lowest level in years. Retrieved from https://kfor.com/2017/09/09/oklahoma-county-jail-population-falls-below-2000-inmates-lowest-level-in-years/ ; and Prison Policy Initiative. (n.d.). State profiles: Oklahoma profile. Retrieved from https://www.prisonpolicy.org/profiles/OK.html
p. 96: Studies suggest community members will be safer and healthier as a result of criminal justice reform. Fishman, N., Kall, K., Silber, R., LaChance, J., Dershowitz, H., & Roberts, S. (2016, December). Greater Oklahoma City Chamber Criminal Justice Reform Task Force: Report and recommendations. New York, NY: Vera Institute of Justice. Retrieved from https://www.vera.org/downloads/publications/OK-chamber-final-report.pdf
p. 96: Crime rates in Oklahoma City trended down from historical highs in 2008 to 2010 and leveled off through 2017. Macrotrends LLC. (n.d.). Oklahoma City, OK, crime rate: 1999–2018. Retrieved from https://www.macrotrends.net/cities/us/ok/oklahoma-city/crime-rate-statistics
p. 96: Addressing entrenched community problems requires cooperation among stakeholders who may have limited experience and represent competing interests. Michener, L., Castrucci, B. C., Bradley, D. W., Hunter, E. L., Thomas, C. W., Patterson, C., & Corcoran, E. (Eds.). (2019). The practical playbook II: Building multisector partnerships that work. New York, NY: Oxford University Press.
p. 97: Quote from Waterford.org. Waterford.org. (2019, January 15). How collaborative philanthropy makes a social impact. https://www.waterford.org/education/how-collaborative-philanthropy-makes-a-social-impact/
pp. 97–98: Three ways in which philanthropies operate to pursue goals and create value for the purpose of furthering a social change agenda aimed at improving communities. Powell, A, Wolf Ditkoff, S., & Twersky, F. (2019, July 10). How philanthropic collaborations succeed, and why they fail. Retrieved from https://ssir.org/articles/entry/how_philanthropic_collaborations_succeed_and_why_they_fail#
p. 98: Effective partnerships and collaborations almost always require a backbone organization. Kania, J., & Kramer, M. (2011, Winter). Collective impact. Retrieved from https://ssir.org/articles/entry/collective_impact
p. 98: Collaborative philanthropy can chart a path to solve thorny societal problems. Wymer, W. W., Jr., & Samu, S. (2003). Dimensions of business and nonprofit collaborative relationships. Journal of Nonprofit & Public Sector Marketing, 11(3), 3–22.
p. 98: An organization’s success may depend on embedding social initiatives into its long-term strategy and core operations. Hess, D., Rogovsky, N., & Dunfee, T. W. (2002). The next wave of corporate community involvement: Corporate social initiatives. California Management Review, 44(2), 110–125.
p. 98: For all collaborators, the major value is achieving community improvement. Waterford.org. (2019, January 15). How collaborative philanthropy makes a social impact. https://www.waterford.org/education/how-collaborative-philanthropy-makes-a-social-impact/
p. 99: Box 5.1. Powell, A, Wolf Ditkoff, S., & Twersky, F. (2019, July 10). How philanthropic collaborations succeed, and why they fail. Retrieved from https://ssir.org/articles/entry/how_philanthropic_collaborations_succeed_and_why_they_fail#
p. 99: Much more than grantmaking and gift-giving are required to achieve the desired impact of collaborative philanthropy. Wolf Ditkoff, S. (n.d.). The long spoon problem: Five models of philanthropic collaboration. Retrieved from https://www.bridgespan.org/insights/library/philanthropy/five-models-of-philanthropic-collaboration
p. 100: Box 5.2: Source: K. Williams, The Sherwood Foundation, personal communication, January 16 and 31 and February 3, 2020.
p. 101: The evolution of corporate philanthropy. Hess, D., Rogovsky, N., & Dunfee, T. W. (2002). The next wave of corporate community involvement: Corporate social initiatives. California Management Review, 44(2), 110–125.
p. 101: Spending, endowment, and employment of healthcare systems and educational institutions. Howard, T., & Norris, T. (2015, November 30). Can hospitals heal America’s communities?: “All in for mission” is the emerging model for impact. Takoma Park, MD: The Democracy Collaborative. Retrieved from https://democracycollaborative.org/learn/publication/can-hospitals-heal-americas-communities-0
pp. 101–102: Through several strategies, UMMHC embraced the anchor framework. Al Kasir, A., & Coles, E. (2019). Anchoring health beyond clinical care: UMass Memorial Health Care’s Anchor Mission Project (Harvard University T.H. Chan School of Public Health, PH9-010). Retrieved from https://alumni.sph.harvard.edu/s/1319/images/gid2/editor_documents/mhcm_alumni/ummhc_case_study.final_formatted.pdf?gid=2&pgid=61&sessionid=853befab-ac6e-430f-90fe-ce5b7d64acf8&cc=1
p. 102: Annual spending on goods and services by hospital systems and institutions of higher education. American Hospital Association. (2018, June). Hospitals are economic anchors in their communities. Retrieved from https://www.aha.org/system/files/2018-06/econ-contribution-2018.pdf ; and The Democracy Collaborative. (2018, April 10). The Democracy Collaborative and the Coalition of Urban and Metropolitan Universities (CUMU) launch the higher education anchor mission initiative in partnership with 31 colleges and universities. Retrieved from https://democracycollaborative.org/learn/blogpost/democracy-collaborative-and-cumu-launch-higher-education-anchor-mission-initiative
p. 102: Cleveland Clinic. Healthcare Anchor Network. (2020, January 8). Inclusive, local procurement: Direct the money your institution already spends to support an inclusive, local business ecosystem. Retrieved from https://healthcareanchor.network/2020/01/inclusive-local-procurement-overview/
p. 103: Metropolitan State University. Central Corridor Anchor Partnership. (n.d.). Procurement: Securing regional prosperity through spending more with Central Corridor businesses. Retrieved from https://www.centralcorridoranchorpartnership.org/aboutprocurement ; Metropolitan State University. (n.d.). Anchored in place: Community wealth and vitality. Retrieved from https://www.metrostate.edu/community/partnerships-and-outreach/wealth-and-vitality ; and P. Hang, Hmong American Farmers Association, personal communication, June 18, 2019.
p. 103: Virginia Commonwealth University. Virginia Commonwealth University, Office of Procurement Services. (n.d.). Supplier diversity/SWaM. Retrieved from https://procurement.vcu.edu/our-services/supplier-diversity--swam/
p. 103: RWJBarnabas Health. D. Candelejo, RWJBarnabas Health, personal communication, December 30, 2019.
pp. 103–104: Fairview Health Services. L. Beeth, Fairview Health Services, personal communication, February 7, 2020.
p. 104: Rutgers University–Newark. Rutgers University–Newark. (n.d.). An anchor institution. Retrieved from https://www.newark.rutgers.edu/anchor-institution-4 ; and Rutgers University–Newark. (n.d.). Rutgers University–Newark: Where opportunity meets excellence—Strategic plan 2014. Retrieved from https://law.rutgers.edu/sites/law/files/attachments/rutgers_strategic_plan.pdf
p. 104: CommonSpirit Health (legacy Dignity Health). U.S. Department of Housing and Urban Development. (n.d.). Dignity Health’s Community Investment Program addresses the social determinants of health. Retrieved from https://www.huduser.gov/portal/casestudies/study-08222017.html
p. 104: Bon Secours Mercy Health. Mercy Housing and Low Income Investment Fund. (2017). Innovative models in health and housing. Retrieved from https://www.liifund.org/wp-content/uploads/2017/08/Health-and-Housing-LIIF-Mercy-Report-2017.pdf
p. 105: University Hospitals Rainbow Center for Women and Children. Healthcare Anchor Network. (2019, November 5). Health system leaders announce over $700 million in investments to address health, housing & economic inequalities through community wealth building [Press release]. Retrieved from https://www.healthcareanchor.network/news-and-updates/health-system-leaders-announce-over-700-million-in-investments-to-address-health-housing-economic-inequalities-through-community-wealth-building
p. 105: Quicken Loans. Feloni, R. (2018). Billionaire Dan Gilbert has already bet $5.6 billion on Detroit’s future, but money can’t solve his biggest challenge. Retrieved from https://www.businessinsider.com/quicken-loans-dan-gilbert-detroit-2018-8
p. 106: Prudential Financial. Roots in the community. Prudential Financial. (n.d.). Redefining anchor institutions. Retrieved from https://www.prudential.com/links/about/corporate-social-responsibility/newark/anchor-institutions
p. 106: Quote from Lata Reddy. Prudential Financial. (n.d.). Q&A with Lata Reddy, Head of the Office of Corporate Social Responsibility. Retrieved from https://www.prudential.com/links/about/corporate-social-responsibility/newark/anchor-institutions/qa-lata-reddy
p. 106: New Orleans Business Alliance (NOLABA). Quote about goals. ProsperityNOLA. (2013, June). ProsperityNOLA: A plan to drive economic grown for 2018. Retrieved from https://www.nolaba.org/wp-content/uploads/2016/03/ProsperityNOLA-Final.pdf
p. 107: Box 5.3. Overall source, including quote from page 7 of Stranahan, S., & Kelly, M. (2019, April 29). Mission-led employee-owned firms: The best of the best. Retrieved from https://democracycollaborative.org/content/mission-led-employee-owned-firms-best-best

## Chapter 6 Data Steps for Businesses and Partners to Address the U.S. Health Disadvantage and Monitor the Business Impact

p. 116: Box 6.1: Source: K. Vijayan and J. Fassbender, personal email communication, February 5, 2020.
p. 117: Measuring system, workplace policy, and culture changes. HERO Scorecard: HERO Health. (n.d.). HERO Health and Well-Being best practices scorecard in collaboration with Mercer© (HERO scorecard). Retrieved from https://hero-health.org/hero-scorecard/. WELCOA Checklist: WELCOA. (n.d.). Well workplace checklist. Retrieved from https://www.welcoa.org/get-started/checklist/
p. 117: Quote from Centre for Bhutan Studies & GNH. Centre for Bhutan Studies & GNH. (2020). Psychological well-being. Retrieved from http://www.grossnationalhappiness.com/9-domains/psychological-well-being/
p. 117: Several organizations help businesses analyze data in a place-based way. Decosimo, K., Simon, M. C., & Matthews, G. W. (2017). GIS mapping of social determinants of health as a tool to facilitate community collaborations. Retrieved from https://cdr.lib.unc.edu/concern/scholarly_works/n870zs78d ; Baase, C., Flynn, J., Goetzel, R., Pronk, N., Terry, P., & White, J. M. (2014, June). Environmental scan: Measuring a culture of health. Retrieved from https://hero-health.org/wp-content/uploads/2014/12/Environmental-Scan-Measuring-a-Culture-of-Health.pdf ; and Baase, C., Pronk, N., & Noyce, J. (2014, January). Environmental scan: The role of corporate America in community health and wellness. Retrieved from https://hero-health.org/wp-content/uploads/2014/12/HERO-EnvScanFinaltoIOM.pdf
p. 117: Businesses are using place-based data in many ways. Map the value chain and understand total value or total return on investment: Porter, M. E., & Kramer, M. R. (2011). Creating shared value. Harvard Business Review, 89, 62–77 ; and Sustainability and Health Initiative for NetPositive Enterprise. (n.d.). Home page. Retrieved from https://shine.sph.harvard.edu/. Develop a balanced portfolio of strategies: Institute for Healthcare Improvement. (n.d.). About Pathways to Population Health. Retrieved from http://www.ihi.org/p2ph. Measure impact over the short-, medium-, and long-terms using process outcomes: 100 Million Healthier Lives. (n.d.). Home page. Retrieved from https://www.100mlives.org/. Understand the overall impact on population health and well-being across people and places: Winmeasures. (n.d.). Home page. Retrieved from https://www.winmeasures.org/
p. 117: Focus of the Shared Value Initiative. Porter, M. E., & Kramer, M. R. (2011). Creating shared value. Harvard Business Review, 89, 62–77 ; and Shared Value Initiative. (n.d.). Home page. Retrieved from https://www.sharedvalue.org/
p. 118: Pathways to Population Health (P2PH). Well Being In the Nation. (n.d.). Home page. Retrieved from http://www.winnetwork.org ; and Institute for Healthcare Improvement. (n.d.). About Pathways to Population Health. Retrieved from http://www.ihi.org/p2ph
p. 118: WIN framework. National Committee on Vital and Health Statistics. (n.d.). Home page. Retrieved from https://ncvhs.hhs.gov/
p. 118: Develop a process for identifying measures that matter. 100 Million Healthier Lives. (n.d.). Home page. Retrieved from https://www.100mlives.org/
p. 119: Box 6.2. Source: Reprinted from page 60 in 100 Million Healthier Lives & National Committee on Vital and Health Statistics. (2019, June). Well Being In the Nation (WIN) Measurement Framework: Measures for improving health, well-being, and equity across sectors. Retrieved from https://www.communitycommons.org/entities/041046ce-f89b-42a4-aa3f-82034a5ac625
p. 120: Materiality assessment. KPMG International Cooperative. (2014, October). Sustainable insight: The essentials of materiality assessment. Retrieved from https://assets.kpmg/content/dam/kpmg/pdf/2014/10/materiality-assessment.pdf
p. 120: Box 6.3. Cantril’s Ladder: Cantril, H. (1965). The pattern of human concerns. New Brunswick, NJ: Rutgers University Press ; and Winmeasures. (n.d.). Well-being of people. Retrieved from https://www.winmeasures.org/statistics/winmeasures/us-wellbeing-of-people. Gallup-Share Well-Being Index: Gallup. (n.d.). How does the Gallup-Sharecare Well-Being Index work? Retrieved from https://www.gallup.com/175196/gallup-healthways-index-methodology.aspx. The measure has reliable, publicly available benchmark data by place in more than 150 countries and many counties in the United States and correlates to business outcomes that matter and major population health outcomes: Deaton, A. (2008). Income, health, and well-being around the world: evidence from the Gallup World Poll. Journal of Economic Perspectives, 22(2), 53–72.19436768
p. 121: Methods for valuing and modeling return over time. Mulgan, G. (2010, Summer). Measuring social value. Stanford Social Innovation Review, 38–43. Retrieved from https://ssir.org/articles/entry/measuring_social_value# ; Organisation for Economic Co-operation and Development & HEC Paris/SnO Center. (2017). Measuring the impacts of business on well-being and sustainability: Selected papers [Compendium]. Retrieved from https://www.oecd.org/statistics/Measuring-impacts-of-business-on-well-being.pdf ; and Shinwell, M., & Shamir, E. (2018). Measuring the impact of businesses on people’s well-being and sustainability: Taking stock of existing frameworks and initiatives (OECD Statistics Working Papers, No. 2018/08). Paris: OECD Publishing. Retrieved from https://www.oecd-ilibrary.org/economics/measuring-the-impact-of-businesses-on-people-s-well-being-and-sustainability_51837366-en
pp. 121–122: The WIN Measurement Framework. 100 Million Healthier Lives & National Committee on Vital and Health Statistics. (2019, June). Well Being In the Nation (WIN) Measurement Framework: Measures for improving health, well-being, and equity across sectors. Retrieved from https://www.communitycommons.org/entities/041046ce-f89b-42a4-aa3f-82034a5ac625
pp. 122–123: Box 6.4. Nehemiah Manufacturing Company owns several brands of its own and also manufactures products for other companies. Patras, E. S. (2020, March 24). Nehemiah Manufacturing’s second chance employment. Retrieved from https://www.greaterohio.org/good-ideas/nehemiah-industries

## Chapter 7 A Way Forward for Community Health and Economic Prosperity

p. 132: Modern innovations have helped to add years of healthy life and lift millions of families out of poverty. Centers for Disease Control and Prevention. (1999). Ten great public health achievements—United States, 1900–1999. Morbidity and Mortality Weekly Report, 48(12), 241–243 ; 10220250 Centers for Disease Control and Prevention. (2011). Ten Great Public Health Achievements—United States, 2001–2010. Morbidity and Mortality Weekly Report, 60(19), 619–623 ; 21597455 Kristof, N. (2019). Why 2018 was the best year in human history! Retrieved from https://www.nytimes.com/2019/01/05/opinion/sunday/2018-progress-poverty-health.html ; and Light, P. C. (2002). Government’s greatest achievements: From civil rights to homeland defense. Washington, DC: Brookings Institution Press.
p. 132: Members of today’s youngest generation may not live longer, more prosperous lives than their parents. Parker, K., Morin, R., & Horowitz, J. M. (2019, March 21). Looking to the future, public sees an America in decline on many fronts. Retrieved from https://www.pewsocialtrends.org/2019/03/21/public-sees-an-america-in-decline-on-many-fronts
p. 132: Box 7.1. America’s public education system continues to produce substantial disparities in educational achievement, largely driven by residential segregation and racial/ethnic differences in family socioeconomic resources: Reardon, S. F. & Fahle, E. M. (2017). State of the Union 2017: Education. Retrieved from https://inequality.stanford.edu/sites/default/files/Pathways_SOTU_2017_education.pdf. African Americans, Hispanics, American Indians, and Alaska Natives of both sexes are underrepresented and undervalued in the workforce to an even greater degree relative to White men: Patten, E. (2016, July 1). Racial, gender wage gaps persist in U.S. despite some progress. Retrieved from https://www.pewresearch.org/fact-tank/2016/07/01/racial-gender-wage-gaps-persist-in-u-s-despite-some-progress/ ; Payscale. (2020). The state of the gender pay gap in 2020: Pay equity analysis can show if your organization pays women less than men for equal work. Retrieved from https://www.payscale.com/data/gender-pay-gap ; and Stych, A. (2019, September 12). Women’s representation on boards reaches a milestone. Retrieved from https://www.bizjournals.com/bizwomen/news/latest-news/2019/09/womens-representation-on-boards-reaches-a.html?page=all
p. 133: All people depend on vital conditions to reach their potential for health, wealth, and well-being. ReThink Health. (2017). Negotiating a well-being portfolio. Retrieved from https://www.rethinkhealth.org/wp-content/uploads/2017/07/Well-Being-Map.pdf ; and Well Being In the Nation Network. (n.d.). Vital conditions. Retrieved from https://winnetwork.org/vital-conditions
p. 135: A thriving company requires thriving communities. Enright, S., & Taylor, A. (2016, October 4). Is it time to overhaul stakeholder engagement? [Blog]. Retrieved from https://www.bsr.org/en/our-insights/blog-view/is-it-time-to-overhaul-stakeholder-engagement
p. 135: Annual healthcare costs to employers of employees with diabetes. Ramsey, S., Summers, K. H., Leong, S. A., Birnbaum, H. G., Kemner, J. E., & Greenberg, P. (2002). Productivity and medical costs of diabetes in a large employer population. Diabetes Care, 25(1), 23–29.11772896
p. 135: Benefits of workers who live in healthy communities. McHugh, M., French, D. D., Farley, D., Maechling, C. R., Dunlop, D. D., & Holl, J. L. (2019). Community health and employee work performance in the American manufacturing environment. Journal of Community Health, 44, 178–184.30194519
p. 135: Consumer habits around purpose-driven companies. Komornicki, S. (2018, May 30). Americans more loyal and willing to defend purpose-driven brands, according to new research by Cone [Press release]. Retrieved from https://www.conecomm.com/news-blog/2018/5/29/americans-more-loyal-and-willing-to-defend-purpose-driven-brands-according-to-new-research-by-cone ; and McCaskill, A. (2015, October 12). Consumer-goods’ brands that demonstrate commitment to sustainability outperform those that don’t. Retrieved from https://www.nielsen.com/us/en/press-releases/2015/consumer-goods-brands-that-demonstrate-commitment-to-sustainability-outperform/
p. 135: Companies that focus heavily on values outperform less values-focused companies by a factor of 10. Mackey, J., & Sisodia, R. S. (2013). Conscious capitalism: Liberating the heroic spirit of business. Boston, MA: Harvard Business School Publishing.
p. 135: Purpose, power, and resources of system stewards. Block, P. (2013). Stewardship: Choosing service over self-interest (2nd ed.). San Francisco, CA: Berrett-Koehler Publishers.
p. 136: Milton Friedman’s belief that corporations have no inherent social responsibilities. Fox, J. (2012, April 18). The social responsibility of business is to increase … What exactly? Retrieved from https://hbr.org/2012/04/you-might-disagree-with-milton ; Kramer, L. (2018, April 26). Beyond neoliberalism: Rethinking political economy. Retrieved from https://hewlett.org/library/beyond-neoliberalism-rethinking-political-economy/ ; McGrath, M., & Konrad, A. (2018, December 10). A surprising push by the invisible hand: Why more companies are doing better by being good. Retrieved from https://www.forbes.com/sites/maggiemcgrath/2018/12/10/wealth-of-the-nation-why-americas-most-valuable-companies-are-also-its-most-ethical/#3a09f6497bb9 ; and Murray, A., & Meyer, D. (2019). CEO daily for May, 9, 2019. Retrieved from https://fortune.com/2019/05/09/china-talks-iran-nuclear-boeing-safety-ceo-daily-for-may-9-2019/
p. 136: All companies must show how they contribute to larger social goals, or risk losing financial support. Coalition for Inclusive Capitalism. (2018, December). EPIC: Embankment Project for Inclusive Capitalism. Retrieved from https://www.epic-value.com/ ; and Fink, L. (n.d.). A fundamental reshaping of finance. Retrieved from https://www.blackrock.com/corporate/investor-relations/larry-fink-ceo-letter
p. 136: Business leaders are repositioning their firms to compete on the basis of how well they generate sustained value for all stakeholders. Business Roundtable. (n.d.). Our commitment statement on the purpose of a corporation. Retrieved from https://opportunity.businessroundtable.org/ourcommitment/
p. 136: Companies are embracing the concept of creating shared value. Porter, M. E., & Kramer, M. R. (2011). Creating shared value: How to reinvent capitalism—and unleash a wave of innovation and growth. Harvard Business Review, 89(1–2), 62–77.
p. 137: Box 7.2. JUST Capital. (2020). Announcing the 2020 rankings of America’s most JUST companies. Retrieved from https://justcapital.com/reports/americas-most-just-companies-2020/
p. 138: UnitedHealthcare. UnitedHealth Group. (2016, February 11). UnitedHealthcare and Chicanos Por La Causa to help Arizonans access quality affordable housing and services that support health and wellness. Retrieved from https://www.unitedhealthgroup.com/newsroom/2016/0211arizonachicanosporlacausapartnership.html ; and HUD User. (n.d.). UnitedHealthcare helps a nonprofit in Phoenix provide Medicaid members with housing and services. Retrieved from https://www.huduser.gov/portal/casestudies/study-071818.html. Quote from Joe Guadio, chief executive office of UnitedHealthcare: Simon, H. (2019, August 1). A health insurer and a CDC collaborate to move the needle on housing and health. Retrieved from https://shelterforce.org/2019/08/21/a-health-insurer-and-a-cdc-collaborate-to-move-the-needle-on-housing-and-health/
p. 138: Quote from Lynda Resnick. The Wonderful Company. (2018, December 19). The Wonderful Company raises minimum wage t $15 per hour for California employees—largest pay increase in company history [Press release]. Retrieved from http://www.wonderful.com/press/THE-WONDERFUL-COMPANY-RAISES-MINIMUM-WAGE-TO-15-DOLLARS-PER-HOUR-FOR-CALIFORNIA-EMPLOYEES.html
p. 139: American Express. Miller, S. (2016, December 14). American Express pushes paid parental leave to 20 weeks for moms and dads. Retrieved from https://www.shrm.org/resourcesandtools/hr-topics/benefits/pages/paid-parental-leave-expands.aspx
p. 139: Positive social and health impacts of quality early childcare. Campbell, F., Conti, G., Heckman, J. J., Moon, S. H., Pinto, R., Pungello, E., & Pan, Y. (2014). Early childhood investments substantially boost adult health. Science, 343(6178), 1478–1485 ; and 24675955 Piper, K. (2018). Early childhood education yields big benefits—just not the ones you think. Retrieved from https://www.vox.com/future-perfect/2018/10/16/17928164/early-childhood-education-doesnt-teach-kids-fund-it
p. 139: Prudential Financial. Beeson, E. (2019, March 30). EDA approves $210 million tax grant to Prudential. Retrieved from https://www.nj.com/business/2012/06/eda_approves_210_million_tax_g.html ; and Prudential Financial Inc. (n.d.). Newark. Our best billion-dollar commitment. Retrieved from https://www.prudential.com/links/about/corporate-social-responsibility/newark/billion-dollar-commitment
pp. 139–140: King Arthur Flour. Stranahan, S., & Kelly, M. (2019, April 29). Mission-led employee-owned firms: The best of the best. Retrieved from https://democracycollaborative.org/content/mission-led-employee-owned-firms-best-best
p. 140: JPMorgan Chase. Feloni, R. (2018, September 12). JPMorgan’s experimental investment in Detroit was so successful that it’s decided to invest $500 million in up-and-coming cities. Retrieved from https://www.businessinsider.com/jpmorgan-launches-advancingcities-initiative-2018-9 ; and JPMorgan Chase. (2019, June 26). JPMorgan Chase exceeds five-year, $150 million investment in Detroit, announces new commitment to reach $200 million total by 2022. Retrieved from https://www.jpmorganchase.com/corporate/news/pr/jpmc-investment-in-detroit.htm
p. 140: Greater Kansas City Chamber of Commerce. Countertobacco.org. (n.d.). Tobacco 21 in Kansas City. Retrieved from https://countertobacco.org/resources-tools/stories-from-the-field/stories-from-the-field-tobacco-21-in-kansas-city/
p. 141: Addressing the U.S. health disadvantage requires support from and collaboration among businesses. Rainie, L., Keeter, S., & Perrin, A. (2019, July 22). Trust and distrust in America. Retrieved from https://www.people-press.org/2019/07/22/trust-and-distrust-in-america/
p. 141: Despite an expansion of the modern American economy, happiness has remained flat or eroded. Easterlin, R. A., McVey, L. A., Switek, M., Sawangfa, O., & Zweig, J. S. (2010). The happiness–income paradox revisited. Proceedings of the National Academy of Sciences, 107(52), 22463–22468 ; Fox, J. (2012). The economics of well-being. Retrieved from https://hbr.org/2012/01/the-economics-of-well-being ; and Ingraham, C. (2019, March 22). Americans are getting more miserable, and there’s data to prove it: We’ve come a long way from the peak happiness of the 1990s, survey finds. Retrieved from https://www.washingtonpost.com/business/2019/03/22/americans-are-getting-more-miserable-theres-data-prove-it/
p. 141: Values for health, wealth, and well-being must be brought into the market. National Academies of Sciences, Engineering, and Medicine. (2018, December 3). Reorienting health care and business investment priorities toward health and well-being: A workshop. Retrieved from https://www.nationalacademies.org/event/12-03-2018/reorienting-health-care-and-business-investment-priorities-toward-health-and-well-being-a-workshop
p. 141: Quote from John Mackey. Page xi in Mackey, J., & Sisodia, R. S. (2013). Conscious capitalism: Liberating the heroic spirit of business. Boston, MA: Harvard Business School Publishing.
p. 141: Other nations are transitioning toward a “well-being economy.” Costanza, R., Caniglia, E., Fioramonti, L., Kubiszewski, I., Lewis, H., Lovins, H., … Wilkinson, R. (2018). Toward a sustainable wellbeing economy. Solutions, 9(2); Diener, E., & Seligman, M. E. P. (2018). Beyond money: Progress on an economy of well-being. Perspectives on Psychological Science, 13(2), 171–175 ; and 29592646 Sturgeon, N. (2019, July). Why governments should prioritize well-being. Retrieved from https://www.ted.com/talks/nicola_sturgeon_why_governments_should_prioritize_well_being
p. 141: New Zealand’s well-being budget. New Zealand Treasury. (2018, November 18). Living standards framework: Introducing the dashboard. Retrieved from https://treasury.govt.nz/publications/tp/living-standards-framework-introducing-dashboard-html ; and Roy, E. A. (2019, May 29). New Zealand ‘wellbeing’ budget promises billions to care for most vulnerable. Retrieved from https://www.theguardian.com/world/2019/may/30/new-zealand-wellbeing-budget-jacinda-ardern-unveils-billions-to-care-for-most-vulnerable
p. 142: Quote about investing in place. Page xi in Kelly, M., & Howard, T. (2019). The making of a democratic economy: Building prosperity for the many, not the few. Oakland, CA: Berrett-Koehler.
p. 142: Quote from Larry Fink. Fink, L. (n.d.). A fundamental reshaping of finance. Retrieved from https://www.blackrock.com/corporate/investor-relations/larry-fink-ceo-letter
p. 142: The relative trajectory of three possibilities (or pathways), each of which has different near- and long-term consequences. Milstein, B. (2017, September 27). Three horizons for health system reform. Presentation at the Annual Meeting of the ReThink Health Ventures Project, Oakland, CA.
p. 143: Table 7.2. Source: Analysis informed by Baase, C. (2015). Testimony of Catherine Baase, M.D., on behalf of the Dow Chemical Company and American Benefits Council. Retrieved from http://get-hwhc.org/wp-content/uploads/2015/06/Baase-Dow-ABC-wellness-testimony012915_final.pdf , and by Bipartisan Policy Center and de Beaumont Foundation. (2019). Good health is good business: The value proposition of partnerships between businesses and governmental public health agencies to improve community health. Washington, DC: Bipartisan Policy Center.
p. 144: Figure 7.1. Relative prominence: Google Books Ngram Viewer. (2020). Health care, public health between 1800 and 2008 in English with smoothing of 10. Retrieved from https://books.google.com/ngrams/. Landmark achievements adapted from: Centers for Disease Control and Prevention. (1999). Ten great public health achievements—United States, 1900–1999. Morbidity and Mortality Weekly Report, 48(12), 241–243 ; 10220250 Centers for Disease Control and Prevention. (2011). Ten Great Public Health Achievements—United States, 2001–2010. Morbidity and Mortality Weekly Report, 60(19), 619–623 ; 21597455 Kristof, N. (2019). Why 2018 was the best year in human history! Retrieved from https://www.nytimes.com/2019/01/05/opinion/sunday/2018-progress-poverty-health.html ; and Light, P. C. (2002). Government’s greatest achievements: From civil rights to homeland defense. Washington, DC: Brookings Institution Press.
p. 145: Figure 7.2. Source: Adapted with permission from International Futures Forum Practice Centre. (n.d.). Three horizons. Retrieved from https://www.iffpraxis.com/three-horizons ; and Milstein, B. (2017, September 27). Three horizons for health system reform. Presentation at the Annual Meeting of the ReThink Health Ventures Project, Oakland, CA.
p. 146: Table 7.3. Source: Milstein, B. (2017, September 27). Three horizons for health system reform. Presentation at the Annual Meeting of the ReThink Health Ventures Project, Oakland, CA. Note A: For more information about next system design, see The Next System Project. (n.d.). About the Next System Project. Retrieved from https://thenextsystem.org/about-next-system-project
p. 146: Quote from Shubhro Sen. Schwartz, T. (2013, April 4). Companies that practice “conscious capitalism” perform 10x better. Retrieved from https://hbr.org/2013/04/companies-that-practice-conscious-capitalism-perform
p. 147: Leaders across the country are stepping up as engaged stewards and forming new partnerships with stakeholders and changemakers. Aspen Institute. (2019, August 2). About Weave: The Social Fabric Project. Retrieved from https://www.aspeninstitute.org/videos/weave-the-social-fabric-project/ ; Brooks, D. (2018, October 18). The neighborhood is the unit of change. No, starfish are not saved one by one. Retrieved from https://www.nytimes.com/2018/10/18/opinion/neighborhood-social-infrastructure-community.html ; Fallows, J. M., & Fallows, D. (2018). Our towns: A 100,000-mile journey into the heart of America (1st ed.). New York, NY: Pantheon Books ; Friedman, T. (2018, July 3). Where American politics can still work: From the bottom up. Retrieved from https://www.nytimes.com/2018/07/03/opinion/community-revitalization-lancaster.html?module=inline ; Fuller, B. (2015). Organizing locally: How the new decentralists improve education, health care, and trade. Chicago, IL: University of Chicago Press ; Katz, B., & Nowak, J. (2018). The new localism: How cities can thrive in the age of populism. Washington, DC: Brookings Institution Press ; and Olmstead, G. (2018, October 8). A renaissance of localism. Retrieved from https://www.theamericanconservative.com/articles/a-renaissance-of-localism/
p. 147: Many partnerships are not as mature as they need to be. Siegel, B., Erickson, J., Milstein, B., & Evans Pritchard, K. (2018). Multisector partnerships need further development to fulfill aspirations for regional system change. Health Affairs, 37(1), 30–37.29309220

## Chapter 8 Report Recommendations

p. 154: Growing expectations for business, as identified by BSR. Enright, S., McElrath, R., & Taylor, A. (2016, October). The future of stakeholder engagement: 2002 Transformative engagement for inclusive business. Retrieved from https://www.bsr.org/reports/BSR_Future_of_Stakeholder_Engagement_Report.pdf
p. 155: Stewardship refers to a company managing its impact on society. Lawler, E. E. III. (2015, September 22). Corporate stewardship. Retrieved from https://www.forbes.com/sites/edwardlawler/2015/09/22/corporate-stewardship/#430c75b2b257
p. 155: Business might be the most powerful institution on earth. Babic, M., Heemskerk, E., & Fichter, J. (2018, July 10). Who is more powerful—States or corporations? Retrieved from https://theconversation.com/who-is-more-powerful-states-or-corporations-99616
p. 155: Visa’s investments in programs to strengthen educational outcomes. Ryssdal K., & McHenry, S. (2020, June 30). Visa CEO: “The world has changed dramatically.” Retrieved from https://www.marketplace.org/2020/06/30/visa-ceo-the-world-has-changed-dramatically/
p. 155: Using hiring and procurement tools to strengthen communities and explore opportunities to unleash untapped potential. Prahalad, C. K., & Hart, S. L. (2002, January 10). The fortune at the bottom of the pyramid: Low-income markets present a prodigious opportunity for the world’s wealthiest companies—to seek their fortunes and bring prosperity to the aspiring poor. Retrieved from https://www.strategy-business.com/article/11518?gko=9b3b4
p. 157: Starbucks’ “Create Jobs for the USA” collaboration with Opportunity Finance Network. Richardson, S. (2016, September 8). The Create Jobs for USA Program. Retrieved from https://www.bostonfed.org/publications/communities-and-banking/2016/fall/the-create-jobs-for-usa-program.aspx
p. 158: Intel’s investment in education. Porter, M. E., Hills, G., Pfitzer, G., Patscheke, S., & Hawkins, E. (n.d.). Measuring shared value: How to unlock value by linking social and business results. Retrieved from https://www.hbs.edu/faculty/Publication%20Files/Measuring_Shared_Value_57032487-9e5c-46a1-9bd8-90bd7f1f9cef.pdf

## Business Perspectives

p. 166: Connection between what students learn in the classroom and how it can have a positive impact on their futures. Centene Corporation. (n.d.). Case study: Ferguson. Retrieved from https://www.centene.com/why-were-different/local-partnerships/transforming-communities/case-study.html
p. 168: Interventions to help identify and manage unmet social needs may improve health by lowering stress levels and increasing positive health behaviors. Thompson, T., McQueen, A., Croston, M., Luke, A., Caito, N., Quinn, K., & Kreuter, M. W. (2019). Social needs and health-related outcomes among Medicaid beneficiaries. Health Education & Behavior, 46(3), 436–444.30654655
p. 169: Quote from Sacramento Mayor Steinberg. Centene Corporation. (2019, March 11). Centene dedicates cornerstone of new Sacramento campus. Retrieved from https://www.centene.com/news/centene-dedicates-sacramento-campus.html
p. 181: Frequency of nutrition-related health problems among Native Americans. Echo Hawk Consulting (2015). Feeding ourselves: Food access, health disparities, and the pathways to healthy Native American communities. Longmont, CO: Echo Hawk Consulting. Retrieved from http://www.heart.org/idc/groups/heart-public/@wcm/@adv/documents/downloadable/ucm_475566.pdf
p. 217: Business for Social Responsibility. Approach/role for business: Business for Social Responsibility. (2018). Healthy business metrics guide. Retrieved from https://healthybusiness.bsr.org/files/Healthy_Business_Metrics_Guide.pdf. Key distinguishing features: Healthy Business Coalition. (n.d.). What is the Healthy Business Coalition? Retrieved from https://healthybusiness.bsr.org/about-us
p. 218: Business Group on Health. Approach/role for business: Quote from Business Group on Health. (n.d.). Well-being and Workplace Strategy Institute: Mission and objectives. Retrieved from https://www.businessgrouphealth.org/get-involved/institutes-committees/well-being-and-workforce-strategy-institute
p. 219: Global Reporting Initiative. Approach/role for business: Quote from GRI. (n.d.). A culture of health for business. Retrieved from https://www.globalreporting.org/cultureofhealthforbusiness/Pages/default.aspx. Recommended practices/process measures: Quote from GRI. (n.d.). A culture of health for business. Retrieved from https://www.globalreporting.org/cultureofhealthforbusiness/Pages/default.aspx ; and COHBPS from GRI & Robert Wood Johnson Foundation. (2019, April). A culture of health for business: Guiding principles to establish a culture of health for business. Retrieved from https://www.globalreporting.org/cultureofhealthforbusiness/Pages/default.aspx
p. 220: Health Enhancement Research Organization (HERO). Approach/role for business: Health Enhancement Research Organization. (2019). Social determinants of health—An employer priority. Retrieved from https://hero-health.org/wp-content/uploads/2019/09/HERO_HWHC_SDOH_Report_FINAL_090419.pdf ; Baase, C., Flynn, J., Goetzel, R., Pronk, N., Terry, P., & White, J. M. (2014, June). Environmental scan: Measuring a culture of health. Retrieved from https://hero-health.org/wp-content/uploads/2014/12/Environmental-Scan-Measuring-a-Culture-of-Health.pdf ; and Baase, C., Pronk, N., & Noyce, J. (2014, January). Environmental scan: The role of corporate America in community health and wellness. Retrieved from https://hero-health.org/wp-content/uploads/2014/12/HERO-EnvScanFinaltoIOM.pdf. Recommended practices/process measures: HERO Health. (n.d.). HERO Health and Well-Being best practices scorecard in collaboration with Mercer© (HERO scorecard). Retrieved from https://hero-health.org/hero-scorecard/. Outcomes defined and measured: Health Enhancement Research Organization and Population Health Alliance. (2018). Program measurement and evaluation guide: Core metrics for employee health management. Retrieved from https://populationhealthalliance.org/wp-content/uploads/2018/02/pha-executive-summary.pdf ; and Gallup. (n.d.). How does the Gallup-Sharecare Well-Being Index work? Retrieved from https://www.gallup.com/175196/gallup-healthways-index-methodology.aspx
p. 221: National Alliance for Healthcare Benefit Coalitions (National Alliance). Approach/role for business: The National Alliance on Healthcare Purchaser Coalitions. (n.d.). Wellbeing Initiative. Retrieved from https://www.nationalalliancehealth.org/initiatives/initiatives-national/wellbeing. Recommended practices/process measures: Pitts, J. S., Rehayem, M., Checkley, J., Frank, S., & Thompson, M. (2019). Mental health & wellbeing in today’s workforce. Retrieved from https://connect.nationalalliancehealth.org/HigherLogic/System/DownloadDocumentFile.ashx?DocumentFileKey=c0a2c8dc-2160-f42e-fef2-f7ab87327d8a
p. 222: National Wellness Institute (NWI). Outcomes defined and measured: Quote from National Wellness Institute. (n.d.). Home page. Retrieved from https://www.nationalwellness.org/
p. 222: NIOSH/CDC. Approach/role for business: Respective quotes from National Institute for Occupational Safety and Health. (2018). What is total worker health? Retrieved from https://www.cdc.gov/niosh/twh/default.html ; and Centers for Disease Control and Prevention. (2019, November 3). Worksite Health ScoreCard. Retrieved from https://www.cdc.gov/workplacehealthpromotion/initiatives/healthscorecard/index.html
p. 223: Pathways to Population Health. Approach/role for business: Institute for Healthcare Improvement. (n.d.). About Pathways to Population Health. Retrieved from http://www.ihi.org/p2ph
p. 224: Robert Wood Johnson Foundation. Approach/role for business: Robert Wood Johnson Foundation. (n.d.). Building a culture of health. Retrieved from https://www.rwjf.org/en/how-we-work/building-a-culture-of-health.html
p. 225: Shared Value Initiative. Approach/role for business: Quote from Shared Value Initiative. (n.d.). Home page. Retrieved from https://www.sharedvalue.org/. Outcomes defined and measured: Quote from Dille, S. (2015, September 23). Good health is a prerequisite for sustainable development. Retrieved from https://www.sharedvalue.org/groups/good-health-prerequisite-sustainable-development
p. 226: Sustainability and Health Initiative for NetPositive Enterprise (SHINE). Approach/role for business: Sustainability and Health Initiative for NetPositive Enterprise. (n.d.). Home page. Retrieved from https://shine.sph.harvard.edu/. Other outcomes defined/measured: Domains of well-being in VanderWeele, T. J., McNeely, E., & Koh, H. K. (2019). Reimagining health—flourishing. JAMA, 321(17), 1667–1668 ; and 30933213 business metrics in Barwinski, K., McNeely, E., & Norris, G. (2016). Shining a light on worker well-being. Ideas from the SHINE NetPositive Summit. Boston, MA: Harvard School of Public Health, The Center for Health and the Global Environment. Retrieved from https://projects.iq.harvard.edu/files/shine/files/workerwellbeing.pdf
p. 227: Well Being In the Nation (WIN) Measurement Framework. Approach/role for business: Winmeasures. (n.d.). Home page. Retrieved from https://www.winmeasures.org/
p. 228: Well Being In the Nation (WIN) Network. Approach/role for business: Well Being In the Nation. (n.d.). Home page. Retrieved from http://www.winnetwork.org. Recommended practices/process measures: Well Being In the Nation. (n.d.). Vital conditions. Retrieved from https://winnetwork.org/vital-conditions
p. 229: Wellness Councils of America (WELCOA). Approach/role for business: WELCOA. (n.d.). Well workplace checklist. Retrieved from https://www.welcoa.org/get-started/checklist/ ; and WELCOA. (2019). Well Workplace Awards: Users guide. Retrieved from https://www.welcoa.org/wp/wp-content/uploads/2019/12/Well-Workplace-Awards-Users-Guide.pdf
p. 230: World Health Organization. Approach/role for business: World Health Organization. (n.d.). Healthy workplaces: A WHO global model for action. Retrieved from https://www.who.int/occupational_health/healthy_workplaces/en/. Recommended practices/process measures: Quote from Grad, F. P. (2002). The preamble of the constitution of the World Health Organization. Bulletin of the World Health Organization, 80(12), 981–984.12571728

## Exemplars

pp. 20–21: Belden, Inc.: Pathways to Employment. Information was obtained by Gerry Yemen, University of Virginia Darden School of Business, during interviews conducted specifically for this report November 18, 2019.
p. 36: Partnership for the Bay’s Future: A High-Impact Model for Investment. One million new jobs in the next 20 years: Plan Bay Area 2040. (n.d.). Forecasting the future. Retrieved from http://2040.planbayarea.org/forecasting-the-future. Two breadwinners working full- time at $15 an hour can afford to live in only 5% of Bay Area neighborhoods: Partnership for the Bay’s Future. (n.d.). The opportunity. Many paths. More solutions. Retrieved from https://www.baysfuture.org/the-opportunity/. A new investment fund of more than $300 million is attracting additional fund investors with competitive returns: Local Initiatives Support Corporation. (2019). Bay Area philanthropy, business, and community advocates unite to launch landmark regional housing partnership [Press release]. Retrieved from http://www.lisc.org/our-stories/story/protect-preserve-produce-landmark-housing-partnership-arrives-bay-area
pp. 56–57: Hyatt Hotels Corporation: An Opportunity Partnership. Information was obtained by Gerry Yemen, University of Virginia Darden School of Business, during interviews conducted specifically for this report on November 25, 2019.
pp. 82–83: Reinvestment Fund: A CDFI Uses Data to Expand Food Retail in Ohio. Information was obtained from K. Vijayan and J. Fassbender via personal email communication, February 5, 2020.
pp. 110–111: The Chickasaw Nation: Investing in Community. Information and quotes were obtained by Gerry Yemen, University of Virginia Darden School of Business, during interviews conducted specifically for this report on November 29, 2019.
pp. 126–127: Greyston Bakery: Baking With Purpose. Information was obtained by Gerry Yemen, University of Virginia Darden School of Business, during interviews conducted specifically for this report on November 25, 2019.
pp. 148–149: Bank of America: The Path to Participation. Information and quotes were obtained by Gerry Yemen, University of Virginia Darden School of Business, during interviews conducted specifically for this report November 14, 2019.
pp. 160–161: Grads of Life: Helping Businesses Build a Talent Pipeline. Information and quotes were obtained by Gerry Yemen, University of Virginia Darden School of Business, during interviews conducted specifically for this report on December 9, 2019.