# APPENDIX B Environmental Scan of Business Approaches to Improve Health and Well-Being

Table B.1 Environmental scan of business approaches to improve health and well-being

Organization/Framework/Initiative | Approach/Role for Business | Recommended Practices/Process Measures | How Are Health and Well-Being and Other Outcomes Defined/Measured? | Key Distinguishing Features | Impact on…
Organization/Framework/Initiative | Approach/Role for Business | Recommended Practices/Process Measures | How Are Health and Well-Being and Other Outcomes Defined/Measured? | Key Distinguishing Features | People | | Places | | Equity
Organization/Framework/Initiative | Approach/Role for Business | Recommended Practices/Process Measures | How Are Health and Well-Being and Other Outcomes Defined/Measured? | Key Distinguishing Features | Employee Benefits | Work Environment | Customer Well-Being | Focused Community Impact | Broader Community and System Impact | People/Places not Currently Thriving
Business for Social Responsibility https://www.bsr.org/en/ | ■ A global nonprofit organization that works with its network of more than 250 member companies and other partners to build a just and sustainable world; ■ Published Healthy Business Metrics Guide to help organizations select the guiding metrics for building evidence-based healthy business programs | ■ Defines a healthy business as “a management approach that seeks to create value and optimize performance by improving the health of consumers, employees, and communities”; ■ Healthy Business Coalition companies set a Healthy Business Strategy that identifies priority health issues on which to invest and design breakthrough programs and partnerships to pilot new solutions and scale through partnerships | Takes a broad perspective on health that includes:; ■ Access to care; ■ Near-term outcomes: Demonstrated changes in awareness of, and access to, positive health drivers, demonstrated changes in individuals’ healthy behaviors and actions; ■ Long-term impacts: Measurable changes in population health and community conditions | An international nonprofit organization that provides consulting to the member organizations of its Healthy Business Coalition. | X | X | X | X
Business Group on Health https://www.businessgrouphealth.org/ | A national member-based nonprofit organization that convenes a Well-being and Workforce Strategy Institute whose mission is to “deploy the healthiest, most productive, engaged and competitive workforce possible to boost business performance and empower great people and communities” | Objectives of the Well-being and Workforce Strategy Institute include:; ■ Identify high-impact holistic well-being strategies; ■ Promote strategic leave, flexibilities, and work-life solutions; ■ Realize the value of cross-functional collaboration with teams, including real estate and facilities, safety, diversity and inclusion, corporate social responsibility, and learning and development to advance well-being in all policies; and; ■ Identify and share ways to infuse well-being throughout the organization and compel leaders to embrace a well-being culture and mindset | ■ Recognizes five dimensions of well-being, including social connectedness, emotional health, physical health, financial security, and job satisfaction; ■ Connects employee well-being to business performance metrics such as talent attraction, engagement and retention, customer satisfaction and loyalty, profitability, safety performance, and industry-specific measures | ■ Business Group on Health is a national coalition of large employer organizations; ■ Holds an annual national conference | X | X
Global Reporting Initiative (GRI) https://www.globalreporting.org | Phase I of GRI’s Culture of Health for Business Project, in collaboration with Robert Wood Johnson Foundation (RWJF), sets out “to understand the scientific and technical basis for attributing positive health and business outcomes to an array of business practices—internal programs, policies, benefits, community partnerships, initiatives and the like—that may or may not be primarily directed toward improvements in population health (i.e., Culture of Health Business Practices, or COHBPs).; The project identifies suitable health measures for businesses and investors to use within those COHBPs and contextualizes these measures to promote understanding and use (i.e., the Culture of Health Business Principles). Surveys of corporate health disclosures and of health measures in existing [environmental, social and governance] reporting frameworks and research methodologies provide reference points for this work.” | The GRI Standards are “a powerful tool for the private sector to accrue, track and report environmental, social and governance issues including health-related topics.”; Health determinants:; ■ Individual behavior; ■ Social environment; ■ Biology and genetics; ■ Health services; ■ Physical environment; COHBPs:; ■ Strategy—health culture, responsible corporate political activity, and responsible marketing practices; ■ Policy and benefits—health promotion and wellness; paid family and medical leave; health insurance; equality, diversity, and impartiality; and financial literacy; ■ Workforce and operations—work time, job security, pay practices, occupational health and safety, and physical environment; ■ Community—community environmental impacts, social capital and cohesion, and community involvement. | The GRI standards outline recommended health outcomes, including:; ■ Social well-being; ■ Mental health and well-being; ■ Birth outcomes; ■ Cancer; ■ Other chronic diseases; ■ Health behaviors; ■ Obesity; ■ Cardiovascular; ■ Mortality; Business outcomes:; ■ Economic societal costs; ■ Financial performance; ■ Brand management; ■ Talent management; ■ Productivity; ■ Health and safety | ■ An independent international organization that has pioneered sustainability reporting since 1997; ■ GRI and RWJF have extended their partnership for the follow-on project “Promoting sustainability reporting to create a Culture of Health for Business in the United States” that seeks to “further promote and increase the uptake of sustainability reporting among US-based organizations and through this, create a Culture of Health for Business” | X | X | | X | X
Health Enhancement Research Organization (HERO) https://hero-health.org/ | A nonprofit member-based organization that conducts research on workplace health-promotion practices, including environmental scans on the role of business in impacting social determinants of health, and cultures of health in organizations and communities. | Offers the HERO Health and Well-Being Best Practices Scorecard in Collaboration with Mercer to provide guidance on employee health and well-being best practices.; The HERO Scorecard measures the following practices:; ■ Strategic planning; ■ Organizational and cultural support; ■ Programs; ■ Program integration; ■ Participation strategies; ■ Program measurement and evaluation | The HERO Scorecard measures the following outcomes:; ■ Physical health (biometrics such as blood pressure, height, weight, etc., and existence of chronic conditions); ■ Mental/emotional health; ■ Health behaviors; ■ Health status; HERO published the Program Measurement and Evaluation Guide: Core Metrics for Employee Health Management that lists well-being as a leading and lagging indicator for health risk and financial outcomes and references the Gallup-Sharecare Well-Being Index elements. | ■ Strong focus on conducting and disseminating findings from research.; ■ Offers the online HERO Scorecard as an open-source tool.; ■ Convenes annual think tank gatherings of member organizations and holds an annual forum open to the public. | X | X | | X
National Alliance for Healthcare Benefit Coalitions (National Alliance) https://connect.nationalalliancehealth.org/home | A national nonprofit coalition of regional business groups; Offers several types of membership:; ■ Coalition membership; ■ Affiliate vendor membership; ■ The National Health Leadership Council (NHLC) membership; The National Wellbeing Initiative is one of many National Alliance initiatives. | Identifies six core areas of leverage that employer organizations can use to create comprehensive and strategic approaches to supporting employee mental health and well-being; Developed a Mental Health and Wellbeing Integration Maturity Model. Levers include:; ■ Culture; ■ Leadership; ■ Operations; ■ Connections; ■ Places; ■ Metrics | Recognizes several domains of well-being, including physical, mental, social, spiritual, and financial | ■ The only nonprofit purchaser-led organization with a national and regional structure dedicated to driving health and healthcare value across the country; ■ Holds an annual conference and leadership summits | X | X | | X
National Institute for Occupational Safety and Health (NIOSH) https://www.cdc.gov/niosh/; The Centers for Disease Control and Prevention (CDC) https://www.cdc.gov | NIOSH Total Worker Health® (TWH) is defined as “policies, programs, and practices that integrate protection from work-related safety and health hazards with promotion of injury and illness prevention efforts to advance worker well-being.”; The CDC Worksite Health ScoreCard is an assessment tool “designed and validated to help employers assess the extent to which they have implemented evidence-based health-promotion interventions or strategies at their worksites to improve the health and wellbeing of their employees.” | The CDC Worksite Health ScoreCard measures:; ■ Organizational supports; ■ Occupational health and safety; ■ Maternal health and lactation support; ■ Support for healthy behaviors; ■ Support for health conditions | According to the CDC, “there is no consensus around a single definition of well-being, but there is general agreement that at minimum, well-being includes the presence of positive emotions and moods (e.g., contentment, happiness), the absence of negative emotions (e.g., depression, anxiety), satisfaction with life, fulfillment and positive functioning.” | ■ Under the jurisdiction of the U.S. Department of Health and Human Services; ■ The leading U.S. public health institution | X | X
National Wellness Institute (NWI) https://www.nationalwellness.org/ | Provides worksite wellness certification for wellness professionals, including a Multicultural Competency in Wellness certificate | NWI’s Multicultural Competency in Wellness framework includes:; ■ Personal & family support; ■ Supporting underserved communities and minimizing healthcare disparities; ■ Worksite wellness, including worksite diversity and inclusiveness initiatives and work-life balance components | ■ Defines wellness as “an active process through which people become aware of, and make choices toward, a more successful existence”; ■ Recognizes six dimensions of well-being, including physical, social, intellectual, emotional, occupational, and spiritual | ■ Offers student, individual, and organizational memberships; ■ Holds an annual National Wellness Conference | X | X
Pathways to Population Health http://www.ihi.org/p2ph | ■ Supports businesses to equitably improve the health and well-being of their employees and their communities; ■ Offers a framework and compass to self-assess and take action and a library of associated tools and resources | Offers four interconnected portfolios of population health improvement that are addressed with an equity lens:; People; ■ Improved mental and physical health; ■ Improved social (work environment, financial security, social connection, social determinants) and spiritual (sense of purpose and meaning) well-being; Places; ■ Community health and well-being (focused cross-sector efforts to improve health and well-being); ■ Communities of solutions—addressing root causes of inequitable outcomes, growing leadership of those affected by inequities; Equity; ■ Strategies to take an equity lens overall and by portfolio; ■ Key levers for action include shared stewardship, equity, payment, and data and measurement | Mental, physical, social (both social determinants and social connection) and spiritual (sense of purpose and meaning); Applies these to the well-being of people and places | ■ Tested as applicable across sectors, has engaged 250+ healthcare organizations as businesses in the journey as well as a number of non-healthcare businesses; ■ Useful for development of a strategic portfolio | X | X | X | X | X | X
Robert Wood Johnson Foundation https://www.rwjf.org | Works collaboratively to build a national Culture of Health where everyone has the opportunity to live a healthier life RWJF Action Framework focuses on how companies influence the health of employees, their families, and communities and how they can contribute to a Culture of Health | Outlines three pre-conditions to harness the power of the private sector:; 1. Recognition of the diverse means by which business influences health, well-being, and health equity; 2. New measures need to characterize the breadth of business-related health outcomes and represent the many positive correlations with important measures of business performance; 3. A shift in investment is needed toward those business practices and policies that promote health to reflect both the hidden costs to business of poor population health and opportunities to create business value by treating health as a strategic priority | Includes people’s physical, mental, and social health and the opportunities they have to create meaningful futures; considers basic needs like food, housing, education, employment, and income | Has supported many of the efforts of other organizations and initiatives represented in this table | X | X | X | X | X | X
Shared Value Initiative https://www.sharedvalue.org/about-shared-value | Creating shared value, a concept currently associated with the work of Michael Porter and Mark Kramer and described as “corporate policies and practices that enhance the competitive advantage and profitability of the company while advancing social and economic conditions in the communities in which it sells and operates.” | ■ Reconceiving products and markets: Meeting societal needs through products and addressing unserved or underserved customers; ■ Redefining productivity in the value chain: Changing practices in the value chain to drive productivity through better utilizing resources, employees, and business partners; ■ Enabling local cluster development: Improving the available skills, supplier base, and supporting institutions in the communities where a company operates to boost productivity, innovation, and growth | Health and well-being are core to the creation of shared value: “When someone has strong health they are able to be educated, work, raise families, and be productive. When health is lacking, people become burdens to themselves, their families and societies. Good health is a prerequisite for sustainable development.” | Focus on the broad value proposition hat organizations bring to communities and society | X | X | X | X | X
Sustainability and Health Initiative for NetPositive Enterprise (SHINE) https://shine.sph.harvard.edu/ | ■ Combines academic research with powerful tools to guide corporate responsibility, sustainability, and health and well-being practices across the globe.; ■ Mission is to conduct applied research to inspire positive change in business around the health and well-being of workers all over the world, no matter their occupation | Acknowledges well-being drivers that include:; ■ Meaning and purpose; ■ Learning and challenge; ■ Autonomy and ability to make choices about how to live, work, and play (freedom from excessive demands and pressure, including financial worry); ■ Progress and recognition; ■ Social connectedness; ■ Trust; ■ Respect; ■ Fairness (including gender equality), safety and security; ■ Physical and mental health | Created an instrument that measures several domains of well-being, including:; ■ Mental and physical health; ■ Meaning and purpose; ■ Character; ■ Close social relationships; ■ Financial stability; Recommends business metrics such as retention, absenteeism, productivity, and performance | ■ Collaborates with large organizations to help them create comprehensive approaches that encourage corporate responsibility for worker well-being across the entire supply chain; ■ Works with member organization to conduct research; ■ Holds an annual summit | X | X | X | X | X | X
Well Being In the Nation (WIN) Measurement Framework https://www.winmeasures.org | A multisector, nationally vetted measurement framework that supports businesses to measure a wide range of initiatives while identifying common outcome measures of well-being across initiatives. | ■ Uses core measures, leading indicators, and learning measures that drive population health and well-being improvement across sectors; ■ Recommends adoption of a balanced portfolio of outcome and process measures that captures the well-being of people, the well-being of places, and equity | ■ Organized around the well-being of people and places (related to a community index with 12 domains and associated subdomains in housing, transportation, health, community vitality, economy, etc.); ■ Includes common measures of the well-being of people, places, and equity that are useful across sectors; ■ Balances leading and lagging indicators; ■ Offers measures of equity as its own category and in an integrated way | ■ Advances people-reported outcome measures as core measures that have been tried in business and related to morbidity, mortality, cost, and worker productivity; ■ Has adoption across thousands of organizations across sectors; ■ Offers common methods for measuring the well-being of people, places, and equity | X | X | X | X | X | X
Well Being In the Nation (WIN) Network https://www.winnetwork.org | ■ Brings together 6 interconnected cooperatives with 150+ participating organizations, including strong business representation; ■ Builds on the WIN measures to consider how legacies of trauma and exclusion can be shifted to legacies of inclusion, how the vital conditions everyone needs to succeed can be ensured through shared stewardship, and how the country might shift from an adversity economy to a well-being economy | ■ Aligns with the WIN measures; ■ Addresses seven vital conditions, or properties of places and institutions needed to participate, prosper, and reach their full potential (basic needs for health and safety, belonging and civic muscle, thriving natural world, humane housing, life-long learning, meaningful work and health, and reliable transportation; ■ Recommends an approach to address policies and investments, stories and dialogue, and narrative change as it relates to the drivers of well-being and equity across sectors; ■ Recommends a balanced portfolio of efforts and associated measures related to the well-being of people, places, and equity as well as to policy and investment and narrative change needed to achieve these | ■ Uses the WIN measures as a basis, particularly Cantril’s ladder; ■ Recommends a balanced portfolio of measures related to the well-being of people, places, and equity as well as to policy and investment and narrative change needed to achieve these | ■ Includes a WIN for Business cooperative made up of organizations speaking to hundreds of businesses; ■ Designed as a development and implementation cooperative | X | X | X | X | X | X
Wellness Councils of America (WELCOA) https://www.welcoa.org/ | ■ A member-based organization that offers The Well Workplace Checklist and administers its Well Workplace Awards designed to showcase organizations that are taking a high-impact and innovative approach to improving the health and well-being of their employees; ■ Provides free employer resources and members-only certification courses to help develop wellness professionals; ■ Holds an annual summit | The Well Workplace Checklist measures the following practices:; ■ Committed and aligned leadership; ■ Collaboration in support of wellness; ■ Collecting meaningful data to evolve a wellness strategy; ■ Crafting an operating plan; ■ Choosing initiatives that support the whole employee; ■ Supportive, health-promoting environments, policies, and practices; ■ Conducting evaluation, communicating, celebrating, and iterating | The checklist and overall approach are grounded in a needs-based definition of wellness with the following domains:; ■ Physical and mental health; ■ Meaning; ■ Safety; ■ Connection; ■ Achievement; ■ Growth; ■ Resiliency | ■ Offers the online Well Workplace Checklist as an open-source tool; ■ Approach focuses on training and tools to help wellness and human resources professionals, benefits consultants, and brokers increase engagement, contain costs, and improve the lives of employees | X | X
World Health Organization https://www.who.int | Healthy Workplaces: A Model for Action from WHO represents “a comprehensive way of thinking and acting that addresses work-related physical and psychosocial risks; promotion and support of healthy behaviors; broader social and environmental determinants.” | Defines a healthy workplace as “one in which workers and managers collaborate to use a continual improvement process to protect and promote the health, safety and wellbeing of all workers and the sustainability of the workplace by considering the following, based on identified needs,” including:; ■ Health and safety concerns in the physical and psychosocial work environments; ■ Personal health resources in the workplace; ■ Ways of participating in the community to improve the health of workers, their families, and members of the community | Defines health as “the state of complete physical, mental, and social well-being, and not merely the absence of disease.” | ■ A specialized agency within the United Nations, which gives it global reach and positions it well to contribute to systems-level transformation; ■ Works with a diverse group of global stakeholders including Ministries of Health, government agencies, and other government departments at the national level; ■ Also works with influencers: health partnerships, foundations, intragovernmental and nongovernmental organizations, civil society, media, professional associations, and WHO collaborating centers | X | X | | X | X