# APPENDIX A Tools and Resources

Table A.1 Multiple chapters: Tools and resources

Organization | Link | Type of tool or resource | Description^a^
Asset-Based Community Development Institute (DePaul University) | https://resources.depaul.edu/abcd-institute/resources/Pages/tool-kit.aspx | Repository of community development tools | This toolkit contains a collection of tools and resources and was created by faculty members of the Asset-Based Community Development (ABCD) Institute, as well as by individuals and organizations that embody in their work the principles of the ABCD Institute. The tools are arranged into three general categories: ABCD Talking Point Tools, Asset Mapping Tools, and Facilitating Tools.
Build Healthy Places Network | https://buildhealthyplaces.org/measureup/mapping-tools/ | Repository of community health and development mapping tools | This collection of maps and mapping tools for community health and development helps users identify disparities, examine baseline data, document trends, and much more. Featured tools include The Opportunity Atlas, the California Health Places Index, and the Distressed Communities Index.
Build Healthy Places Network | https://buildhealthyplaces.org/measureup/measurement-tools/ | Repository of community health and development measurement tools | This collection of measurement tools for community health and development provides users with instruments to measure impact and allows them to compare and contrast tools to help them find the ones that best fit their needs. Featured tools include Enterprise Community Partners’ Healthy Housing Outcomes Survey, the St. Louis Federal Reserve’s Community Investment Explorer, and a city health dashboard.
Build Initiative | https://www.buildinitiative.org/CSDToolkit | Community systems development toolkit | This toolkit, which is tailored to the needs of community-based collaboration and organized in systems change theory, is designed to provide accessible, comprehensive resources that support the changing stages and needs of communities engaged in collaborative work. Tools include forms, examples of community level strategies, questions, guidance, samples, processes, and articles.
Centers for Disease Control and Prevention | https://www.cdc.gov/workplacehealthpromotion/tools-resources/workplace-health/mental-health/index.html | Resource about mental health disorders and stress that affect working-age Americans | Website offers strategies for managing mental health and stress in the workplace, along with business success stories and solutions.
Collaborative Toolbox | https://www.collaborativetoolbox.ca/strengthening-communities | Collection of resources on strengthening communities | This collection of resources helps to guide communities in fostering caring relationships, which can make a difference in the life trajectory of a child or youth. Resources include community plans and profiles, reports on specific topics, and press releases, among other types of resources.
Community Tool Box (University of Kansas) | https://ctb.ku.edu/en/table-of-contents/assessment/assessing-community-needs-and-resources | Collection of resources on assessing community needs and resources | This chapter of the Community Tool Box includes an array of resources on assessing community needs and resources. Twenty-four sections in the chapter cover such topics as conducting needs assessment surveys, using tools for community mapping, and using small area analysis to uncover disparities. The broader Community Tool Box resource is also useful for community-building skills.
Community Tool Box (University of Kansas) | https://ctb.ku.edu/en/toolkits | Repository of community development tools | This collection of toolkits from the University of Kansas’s Community Tool Box helps users get a quick start on essential activities in community work. The toolkit covers such topics as creating and maintaining coalitions and partnerships, assessing community needs and resources, developing a framework or model of change, enhancing cultural competence, influencing policy development, and applying for grants, among others.
Federal Reserve Bank of Atlanta | https://www.frbatlanta.org/cweo/data-tools/opportunity-occupations-monitor.aspx | Opportunity employment tool | The Opportunity Occupations Monitor displays opportunity employment and its prevalence across labor markets. Opportunity employment is an estimate of the number and share of jobs accessible to workers without a bachelor’s degree that pay more than the national median wage.
National Institute for Occupational Safety and Health | https://www.cdc.gov/niosh/topics/opioids/wsrp/default.html | Tools for a workplace-supported recovery program | Workplaces are a critical point of contact for Americans struggling with or recovering from a substance use disorder. Ideally, workplaces provide individual-, family-, and community-level support and improve the well-being of workers. Workplaces should create work environments that proactively prevent substance misuse, reduce stigma, and encourage treatment and sustained recovery.
National Safety Council | https://nsc.org/drugsatwork | A substance use cost-calculator for employers | The National Safety Council collaborated with NORC at the University of Chicago, an independent research institution, to update The Real Cost of Substance Use to Employers tool, which was originally developed in 2017 with national nonprofit Shatterproof. This cost calculator is an easy-to-use tool that provides business leaders with specific information about the cost of substance use (including prescription drug use and misuse, alcohol use and misuse, opioid and heroin addiction, and use of other illicit drugs and cannabis) in their workplace based on size of employee base, industry, and state.
Organisation for Economic Cooperation and Development (OECD) | https://www.oecd-ilibrary.org/economics/measuring-the-impact-of-businesses-on-people-s-well-being-and-sustainability_51837366-en | Selected papers on measuring the impacts of business on well-being and sustainability | The OECD Statistics Working Paper Series offers a collection of publications about measuring or reporting on business’ impact, or certain aspects of it. In particular, this paper (Measuring the impact of businesses on people’s well-being and sustainability: Taking stock of existing frameworks and initiatives by Michal Shinwelli and Efrat Shamiri) shows that despite the proliferation of information and frameworks to measure these impacts, there is currently no common understanding and practice on how to assess the performance of businesses in different social and environmental areas. Building on OECD’s work on measuring well-being at the national level, the paper aims at better understanding how businesses can impact people’s well-being and sustainability. It contributes to, and complements, other initiatives undertaken by OECD on responsible business conduct and inclusive growth. This analysis is a first attempt at extending to businesses the approach used by OECD to assess and benchmark the well-being performance of countries and subnational regions, in view of creating a common language and improving the quality, comparability, and coherence of information on the impact of businesses on societal progress and people’s life.
The Rippel Foundation, with support from the Robert Wood Johnson Foundation | https://www.rethinkhealth.org/wp-content/uploads/2018/10/RTH-WellBeingPortfolio_InstructionsSummary_10222018.pdf | Well-being portfolio tool | The Negotiating a Well-Being Portfolio exercise is designed to help regional leaders explore how to create a balanced and impactful set of policies, programs, and practices that will transform the system that produces health and well-being in a region. The exercise consists of 12 different portfolio options, each representing a category of policies, programs, and practices that address either urgent needs or vital conditions. This exercise is most effective if users are able to gather major stakeholders from across their region. This exercise assumes that users have developed a shared vision or value proposition for regional transformation.
Santa Cruz County (California) Business Council | https://sccbusinesscouncil.com/wp-content/uploads/2019/03/Rapid-Re-Housing-Brief.pdf | Rapid Rehousing brief | This brief describes rapid rehousing intervention and its core components, target populations, and effectiveness. The brief also lists some practical considerations, important questions to consider when implementing rapid rehousing, and useful external resources.
Substance Abuse and Mental Health Services Administration | https://www.samhsa.gov/workplace/toolkit | Information to help employers develop and sustain successful drug-free workplace programs | The Drug-Free Workplace Toolkit supports workplace health and safety by creating and maintaining drug-free workplace policies and programs. The policies and programs may include preventing the misuse and abuse of alcohol, tobacco, and other drugs; addressing substance misuse within the context of workplace health and wellness programs; and providing intervention services for employees and their families.
The White House | https://www.whitehouse.gov/sites/whitehouse.gov/files/images/Housing_Development_Toolkit%20f.2.pdf | Housing development toolkit | This toolkit highlights actions that states and local jurisdictions have taken to promote healthy, responsive, affordable, high-opportunity housing markets. These actions include establishing by-right development, taxing vacant land or donating it to nonprofit developers, streamlining or shortening permitting processes and timelines, eliminating off-street parking requirements, allowing accessory dwelling units, establishing density bonuses, enacting high-density and multifamily zoning, employing inclusionary zoning, establishing development tax or value capture incentives, and using property tax abatements.
U.S. Chamber of Commerce Foundation | https://www.uschamberfoundation.org/quick-guides | Tools that help local chambers of commerce and local businesses prepare for and recover from disasters | Created by the U.S. Chamber of Commerce Foundation Corporate Citizenship Center, the Disaster Preparedness and Recovery Quick Guides provide local chambers and small businesses with practical tools and resources to become better prepared for disasters and to better understand what steps to take after such an event occurs.
U.S. Economic Development Administration (EDA) | https://eda.gov/tools/ | Repository of tools and resources for economic development | This is a collection of tools and resources from EDA, which partners with entities to develop and disseminate tools on new and emerging economic development concepts that practitioners and policymakers can utilize to make more informed development decisions. This collection includes two tools designed to help practitioners better identify their cluster assets and an investment analysis tool that helps practitioners prioritize projects. It also includes a tool that provides EDA stakeholders who are interested in measuring distress with an efficient way to calculate whether a county, region, or neighborhood may meet EDA eligibility thresholds for unemployment and income.
University of California, Berkeley, Labor Center | https://laborcenter.berkeley.edu/topic/low-wage-work/labor-standards/minimum-wage/ | Repository of resources and tools on minimum wage and living wage | This website includes several tools and resources focused on minimum and living wages, including a living wage calculator and a basic family budget calculator. It also contains resources on other topics, such as minimum wage ordinances.
United States Interagency Council on Homelessness | https://www.usich.gov/tools-for-action/ | Collection of tools for action to address homelessness and related issues | This database of resources on homelessness includes a variety of resources, including briefs, fact sheets, reports, tools, and webinars. Users can filters search results by several different parameters. This database was created and is managed by the U.S. government.
Well Being In the Nation (WIN) | https://www.winmeasures.org/statistics/winmeasures | Website with measures of community well-being | This website describes the WIN measures, which show connections between social conditions, health, community, and well-being. It gives an overview of core measures of the well-being of people, the well-being of places, and equity, and it highlights leading indicators of well-being in such domains as economics, housing, and education.
Well Being In the Nation (WIN) Network | https://winnetwork.org/vital-conditions | Website with a collection of resources on vital conditions | The WIN Network presents an overview of the Vital Conditions for Well-Being framework and offers separate resources for each vital condition. The vital conditions included in the framework are basic needs for health and safety, life-long learning, meaningful work and health, humane housing, reliable transportation, and a thriving natural world.

a Descriptions are used in full or adapted from content in the respective tool or resource or from content on the respective organization’s website.

Table A.2 Chapter 1: Tools and resources

Organization | Link | Type of tool or resource | Description^a^
Center for American Progress | https://www.americanprogress.org/issues/poverty/reports/2015/03/23/109460/expanding-opportunities-in-americas-urban-areas/ | Article on expanding opportunities in America’s urban areas | This article frames the conversation on expanding opportunities in urban areas, and presents five policy strategies that outline specific ways to address some of the challenges facing urban areas. It also includes a subsection of related resources for each of the five policy strategies.
John Hancock Insurance Company | https://www.johnhancockinsurance.com/life-expectancy-calculator.html | Life expectancy calculator | This tool allows users to predict the number of years they can expect to live based on information they input for certain health and behavioral parameters. This tool was developed by an insurance company, and it is primarily intended for individuals who are interested in learning about how life insurance can help them plan for today and the future.
National Safety Council (NSC), Shatterproof, and NORC at the University of Chicago | https://www.nsc.org/forms/substance-use-employer-calculator | Substance use cost calculator | This tool provides business leaders with specific information about the cost of substance use (including prescription drug use and misuse, alcohol use and misuse, opioid and heroin addiction, and use of other illicit drugs and marijuana) in their workplace based on the size of their employee base, industry, and state.
The Kresge Foundation | https://kresge.org/resources and https://kresge.org/resource/lessons-from-the-healthy-futures-fund | Website with information about expanding opportunities in America’s cities | Developed by The Kresge Foundation, The Opportunity Fund is a portfolio of investments that promotes fairness and equity, justice, and opportunity through efforts to protect and strengthen democratic institutions, advance civil rights, counteract hate and racism, support immigrant and refugee communities, and provide legal supports to underserved communities.

a Descriptions are used in full or adapted from content in the respective tool or resource or from content on the respective organization’s website.

Table A.3 Chapter 2: Tools and resources

Organization | Link | Type of tool or resource | Description^a^
Aspen Institute | https://www.aspeninstitute.org/programs/economic-opportunities-program/ | Website on The Aspen Institute’s Economic Opportunities Program | This website provides information and resources about the Economic Opportunities Program (EOP), which advances strategies, policies, and ideas to help low- and moderate-income people thrive in a changing economy. This program recognizes that race, gender, and place intersect with and intensify the challenge of economic inequality, and it addresses these dynamics by advancing an inclusive vision of economic justice.
Child Welfare Information Gateway | https://www.childwelfare.gov/topics/systemwide/youth/development/promoting/ | Collection of resources for promoting positive youth development | This collection or resources focuses on positive youth development. It includes a video on how caring adults promote positive youth development, a curriculum for youth work professionals, and a youth leadership toolkit. This set of resources is intended to help state and local organizations develop and sustain positive youth development programs in their communities.
Opportunity Nation | https://opportunitynation.org/ | Interactive economic mobility mapping tool | The Opportunity Index is an interactive tool designed to measure opportunity by connecting multiple economic, educational, and civic factors. It allows users to learn about the economic mobility of their county and state, as well as national trends. The tool was developed by Opportunity Nation, a bipartisan, cross-sector, national campaign to expand economic mobility and restore the American dream.
U.S. Census Bureau, Harvard University, and Brown University | https://opportunityatlas.org/ | Economic mobility mapping tool | The Opportunity Atlas allows users to trace the roots of today’s affluence and poverty back to the neighborhoods where people grew up based on anonymous data following approximately 20 million Americans from childhood to their mid-30s. This tool enables users to see which neighborhoods in America offer children the best chance to rise out of poverty and to see where and for whom opportunity has been missing. It is intended to inform the development of local solutions to help more children rise out of poverty.

a Descriptions are used in full or adapted from content in the respective tool or resource or from content on the respective organization’s website.

Table A.4 Chapter 3: Tools and resources

Organization | Link | Type of tool or resource | Description^a^
American Public Transportation Association | http://www.publictransportation.org/tools-calculators/ | Tools and resources for public transportation | This collection of tools and resources includes a Public Transit in Your Community Tool that allows users to search local transit systems across the country, a Fuel Savings Calculator that helps users discover the cost saving benefits of taking public transportation, a Carbon Savings Calculator that calculates the carbon dioxide emissions saved by switching to public transportation, and a Transit Savings Report that shows annual and monthly savings incurred by switching from a car to public transit.
Centers for Medicare & Medicaid Services | https://www.cms.gov/Research-Statistics-Data-and-Systems/Statistics-Trends-and-Reports/Medicare-Provider-Charge-Data/OpioidMap_Medicaid_State | Medicaid state opioid prescribing mapping tool | The Medicaid opioid prescribing mapping tool is an interactive tool that shows state-level geographic comparisons of de-identified Medicaid opioid prescriptions filled in the United States. The mapping tool presents Medicaid opioid prescribing rates for 2017, as well as the change in opioid prescribing rates from 2013 to 2017. The mapping tool allows users to see the number and percentage of opioid prescriptions in order to better understand how this critical issue impacts states nationwide.
Conscious Capitalism | https://www.consciouscapitalism.org/learn-what-we-do | Brief resource about conscious capitalism | This resource defines conscious capitalism and its four tenets, and it explains why there is a need for capitalism to be conscious.
Fisher Investments | https://www.fisher401k.com/plan-options/profit-sharing-plan | Brief overview of 401k profit sharing plans | This webpage offers a brief explanation of 401k profit sharing plans, distinguishes between the different types of plans, and lists benefits of such plans.
Ohio Housing Finance Agency/Ohio Preservation Compact | http://gis5.oit.ohio.gov/housing/ | Affordable housing mapping tool | This affordable housing mapping tool includes information about the demographic characteristics, amenities, and health-related factors in Ohio’s neighborhoods. The tool is intended to inform affordable housing policies. It maps only counties, ZIP codes, and cities in Ohio.
Teachers Credit Union | https://www.tcunet.com/Plan/Calculators/Planning-Calculators/401k-Profit-Sharing-Calculator | 401k profit sharing calculator | This 401k profit sharing calculator allows users to enter information on a several personal finance-related parameters and helps users figure out how much of their salary they might want to set aside for retirement, how fast that money is likely to grow at certain rates of return, and the benefits provided by employer contributions.
U.S. Department of Housing and Urban Development (HUD) | https://egis.hud.gov/affht/ | Affordable housing assessment tool | This affordable housing assessment tool provides users with maps of affordable housing in a specific locality and maps showing how such housing differs by demographic characteristics, job proximity, school proficiency, disability, and other variables. HUD created this tool for Public Housing Agencies to use in conducting and submitting an Assessment of Fair Housing.
U.S. Department of Labor | https://www.dol.gov/sites/dolgov/files/EBSA/about-ebsa/our-activities/resource-center/publications/profit-sharing-plans-for-small-businesses.pdf | Booklet on profit sharing plans for small businesses | This booklet highlights some of the advantages of profit sharing plans and some of the options and responsibilities that employers operating such a plan have. The booklet also includes a profit sharing plan checklist and a list of other potentially useful resources.

a Descriptions are used in full or adapted from content in the respective tool or resource or from content on the respective organization’s website.

Table A.5 Chapter 4: Tools and resources

Organization | Link | Type of tool or resource | Description^a^
Bank of America | https://about.bankofamerica.com/en-us/partnering-locally/cdfi-list.html#fbid=7icjo-DigzF | Community development financial institution (CDFI) locator tool | This search tool can be used to find a CDFI in a certain area or to learn more about how Bank of America is investing in local economies. Users can filter results by loan amount and location.
Columbia University’s Teachers College | https://www.tc.columbia.edu/articles/2019/august/getting-low-income-families-to-higher-opportunity-neighborhoods/ | Article on housing choice vouchers (Section 8) | This article summarizes empirical research showing unprecedented gains from an intervention that reduces common barriers to using housing choice vouchers and helps move low-income families to “higher-opportunity” neighborhoods.
Congressional Research Service | https://fas.org/sgp/crs/misc/RS22389.pdf | Research report on the Low-Income Housing Tax Credit (LIHTC) program | This report provides an overview of the LIHTC program, including the types of credits, the allocation process, and recent legislative developments. It also offers an example to help readers help understand how the LIHTC program is intended to encourage affordable housing development.
Local Initiatives Support Corporation (LISC) | https://www.lisc.org/our-initiatives/financial-stability/bridge-programs/ | Information about LISC’s Bridges to Career Opportunities program | This website delivers a brief overview of LISC’s Bridges to Career Opportunities program and discusses how Citi Foundation has invested in this program.
National Association of Counties | https://www.naco.org/resources/featured/affordable-housing-toolkit-counties | Affordable housing toolkit for counties | This affordable housing toolkit is designed for counties, and it covers such topics as inter-jurisdictional partnerships, funding and financing, planning and zoning, and advocacy resources. It also contains an appendix with information on measuring housing affordability and additional resources on affordable housing development.
National Multifamily Housing Council | https://housingtoolkit.nmhc.org/ | Affordable housing toolkit | This affordable housing toolkit is designed to help policymakers understand the dynamics of the housing market, what drives housing costs up, how state and local policies impact affordability, and what solutions might work in their specific jurisdiction. It is also intended to be used to educate all stakeholders— policymakers, community advocates, urban planners, business groups and more—and to provide apartment firms with the information they need to help advocate effective local housing policies.
New Markets Tax Credit Program | https://www.cdfifund.gov/Pages/mapping-system.aspx | Community development financial institution (CDFI) information mapping system tool | This mapping tool—CDFI Information Mapping System v.3 (CIMS3)—helps users geocode addresses, map census tracts and counties, and determine the eligibility of census tracts and counties under the CDFI Fund’s various program distress criteria. Users of CIMS3 can create and save maps and reports, including Target Market worksheets, and submit saved maps and reports for online applications and other uses. CIMS3 is available in two versions: a limited public-use version and a full version accessed through an organization’s Awards Management Information System account.
Novogradac | https://www.novoco.com/resource-centers/affordable-housing-tax-credits/data-tools/lihtc-mapping-tool | Low-Income Housing Tax Credit (LIHTC) mapping tool | This LIHTC mapping tool helps users find LIHTCs in their area. The tool includes project address, number of units and low-income units, number of bedrooms, year the credit was allocated, year the project was placed in service, whether the project was new construction or rehab, type of credit provided, and other sources of project financing. The information is based on the U.S. Department of Housing and Urban Development’s LIHTC Database, which was last revised as of May 2019. The LIHTC database, created by HUD and available to the public since 1997, contains information on 47,511 properties and almost 3.13 million housing units placed in service between 1987 and 2017.
Novogradac | https://www.novoco.com/resource-centers/new-markets-tax-credits/data-tools/nmtc-mapping-tool | New Markets Tax Credit mapping tool | This mapping tool shows a location’s eligibility for a New Market Tax Credit, as well as the percentage of residents living in poverty, the population, median family income, and other information.
Opportunity Finance Network | https://ofn.org/cdfi-locator | Community development financial institution (CDFI) locator tool | This CDFI locator tool allows users to find an Opportunity Finance Network Member CDFI in their state. The tool allows users to filter CDFIs by organization, areas served, organization type, and lending type.
The Brookings Institution | https://www.brookings.edu/policy2020/bigideas/to-improve-housing-affordability-we-need-better-alignment-of-zoning-taxes-and-subsidies/ | Policy brief on housing policies | This report discusses the importance of better aligning three types of housing policies and addresses challenges related to implementation. The policies are reforming land use regulation to allow smaller, more compact housing; increasing taxes on expensive, underused land; and expanding housing subsidies to low-income households.
U.S. Department of Health and Human Services | https://www.acf.hhs.gov/sites/default/files/fysb/youth_homelessness.pdf | Federal report to Congress about on ending youth homelessness | This report to Congress summarizes the problem of youth homelessness, offers some theoretical perspectives on homelessness, identifies interventions to prevent and ameliorate homelessness, and discusses implications for policy and program development.
U.S. Department of the Treasury | https://www.cdfifund.gov/Pages/default.aspx | Website with a brief overview of the CDFI Fund | This website gives a brief overview of the U.S. Department of Treasury’s CDFI Fund. It discusses what the CDFI Fund does, its program areas, and the impact it makes. The website also includes a few CDFI Fund-related resources and tools, such as compliance and performance reporting resources and a CDFI Information Mapping System (CIMS).
Urban Institute | https://www.urban.org/sites/default/files/publication/98758/lithc_how_it_works_and_who_it_serves_final_2.pdf | Research report on the Low-Income Housing Tax Credit (LIHTC) program | This report outlines the basics of the LIHTC program, including how it works, the various partners involved, how financing is structured, how investors benefit from the program, and who lives in the LIHTC properties. The report also highlights successes of the program and examines the challenges it faces.

a Descriptions are used in full or adapted from content in the respective tool or resource or from content on the respective organization’s website.

Table A.6 Chapter 5: Tools and resources

Organization | Link | Type of tool or resource | Description^a^
American Cancer Society | https://www.fightcancer.org/policy-resources/smoke-free-policies-good-business | Brief about the benefits of smokefree policies for businesses | This brief discusses several ways in which smokefree policies are good for businesses. Some of the points discussed are based on empirical research.
American Cancer Society | https://www.cancer.org/healthy/stay-away-from-tobacco/smoke-free-communities/create-smoke-free-workplace/smoking-in-the-workplace-a-model-policy.html | Website on smoke-free policies | This website offers a brief overview of the benefits of smokefree policies for both employees and employers. It also includes a model smokefree policy.
American Institute of Certified Public Accountants (AICPA) National Commission on Diversity and Inclusion | https://www.aicpa.org/career/diversityinitiatives/downloadabledocuments/recruitment-retention-toolkit.pdf | Recruitment and retention toolkit | This toolkit was written to help leaders understand how recruiting and retaining a diverse workforce can help them better achieve their companies’ overall talent recruitment and retention goals. It is also meant to provide support on how to integrate diversity recruiting and retention techniques into broader day-to-day business and personal activities. This toolkit is aimed at human resource leaders, practice leaders, and others charged with attracting, recruiting, and retaining a diverse workforce in their organization.
American Nonsmokers’ Rights Foundation | https://no-smoke.org/wp-content/uploads/pdf/business-costs-in-smoke-filled-environments.pdf | Resource on business costs in smoke-filled environments | This resource from the American Nonsmokers’ Rights Foundation highlights the costs of doing business in smoke-filled environments. It discusses the effects that smoke-filled workplaces have on profitability, absenteeism and productivity, maintenance, and insurance rates.
Annie E. Casey Foundation | https://www.aecf.org/m/resourcedoc/AECF-ReentryAndBarrierstoEmp-2016.pdf | Report on reentry and barriers to employment for previously incarcerated persons | This report summarizes some of the lessons the Annie E. Casey Foundation learned from its reentry and employment efforts, with insights from dozens of reports and resources on incarceration and reentry, as well as interviews with Casey staff members who worked directly on these investments. It is intended to help inform practitioners, funders, and policymakers who are pursuing strategies that connect formerly incarcerated individuals with employment.
Associated Black Charities | http://www.abc-md.org/new-page | Website on equitable hiring practices | This resource presents questions whose consideration are intended to help everyone in Baltimore’s regional economy start from the same place in their quests to earn a livable wage, raise a stable family, and build wealth for future generations.
Build Health Places Network | https://www.buildhealthyplaces.org/partners/ | Partner finder tool | Partner Finder is a collection of 13 directories intended to help users find community development and health organizations/partners near to them.
Centers for Disease Control and Prevention (CDC) | https://www.cdc.gov/partners/index.html | Collection of tools and resources for public-private partnerships | This CDC website on public–private partnerships is intended to educate users about how they can participate in protecting the health of their organization, their workforce, and the nation. It includes information on partnering with CDC and a collection of tools and resources on public–private partnerships.
Centers for Disease Control and Prevention (CDC) | https://www.cdc.gov/tobacco/data_statistics/fact_sheets/index.htm#by-topic | Collection of smoking-related fact sheets | This collection of fast facts and fact sheets from CDC includes information on cessation, secondhand smoke, smokeless tobacco, the health effects of cigarette smoke, and tobacco marketing, among others. This site is part of CDC’s larger website on smoking and tobacco, which includes a link to the Office on Smoking and Health and a collection of multimedia resources and tools.
City of Minneapolis (Minnesota) | http://www.minneapolismn.gov/www/groups/public/@cped/documents/webcontent/wcmsp-179539.pdf | Guide to inclusive hiring | This guide to inclusive hiring answers such questions as why prioritize inclusive hiring, where can I get assistance, what are the recent trends in recruitment, and how do I know where to start? The guide includes content on framing the business case for inclusion, 10 inclusive hiring principles and practices, and a tool for readers to evaluate their recruiting process.
County of Marin (California) Department of Human Resources | https://www.marincountyhr.org/find-employee-tools/diversitytkmain | Diversity hiring toolkit | This diversity hiring toolkit is intended to provide users with information, tools, and resources to recruit—in partnership with human resources—for employment vacancies, with a focus on building a high-quality and diverse applicant pool and a more inclusive hiring process. It walks users through four steps of the hiring process and includes a collection of additional resources.
de Beaumont | https://www.debeaumont.org/news/2019/new-practical-playbook-provides-roadmap-to-improve-population-health/ | Website for book on building multisector partnerships that work | This website allows interested readers to purchase The Practical Playbook II: Building Multisector Partnerships That Work, which provides a concise set of tools, methods, and examples to support partnerships to improve population health. The playbook is written in practical terms for readers from any background or sector, and it draws from successful partnerships in public health, healthcare, housing, transportation, business, and the faith community— providing practical tips from conception to execution to policy change.
Democracy Collaborative | https://democracycollaborative.org/sites/default/files/downloads/Anchor%2520Collaboratives%2520Report%2520-%2520FINAL-updated.pdf | Report on collaboration with anchor institutions | This report presents information and examples to show the current state of the field of anchor institutions. It discusses anchor collaboratives and their importance, how anchor institutions can be drivers for community development, the regular players in anchor collaboratives, among other topics.
Fidelity Charitable | https://www.fidelitycharitable.org/guidance/philanthropy/impact-investing.html | Website with overview of impact investing | This website provides a quick overview of impact investing, and discusses the types and benefits of impact investing and how to participate in impact investing.
Global Impact Investing Network | https://thegiin.org/impact-investing/need-to-know/ | Website with overview of impact investing | This website gives an overview of impact investing. It discusses the core characteristics of impact investing, who makes impact investments, the results that these investments can achieve, and more. A version of this primer, answering many of the most frequently asked questions about impact investing, is available for download.
National Association of Counties | https://www.naco.org/resources/featured/affordable-housing-toolkit-counties | Affordable housing toolkit for counties | This toolkit on affordable housing is designed for counties, and it covers such topics as interjurisdictional partnerships, funding and financing, planning and zoning, and advocacy resources. It also contains an appendix with information about measuring housing affordability and with additional resources on affordable housing development.
National Multifamily Housing Council | https://housingtoolkit.nmhc.org/ | Affordable housing toolkit | This toolkit on affordable housing is designed to help policymakers understand the dynamics of the housing market, what drives housing costs up, how state and local policies impact affordability, and what solutions might work in their specific jurisdiction. It is also intended to educate all stakeholders— policymakers, community advocates, urban planners, business groups, and more—and to provide apartment firms with the information they need to help advocate effective local housing policies.
Netter Center for Community Partnerships at The University of Pennsylvania | https://www.nettercenter.upenn.edu/sites/default/files/Anchor_Toolkit6_09.pdf | Anchor institutions toolkit | This toolkit is intended as a guide for anchor institutions to rebuild, revitalize, strengthen, and improve their local communities. Each of the tools in this kit was developed and implemented by the University of Pennsylvania, working with stakeholders of West Philadelphia—the university’s local geographic community—including neighborhood associations, city officials and city agencies, local businesses, nonprofit organizations, and institutions of higher education, as appropriate. This toolkit is designed to help anchor institutions formulate the right questions and seek effective answers that will lead to collaborative actions that benefit both institutions and communities.
Public-Private-Partnership Legal Resource Center, World Bank Group | https://ppp.worldbank.org/public-private-partnership/overview/practical-tools | Repository of tools and resources for public– private partnerships | This website offers practical guidance for structuring a public-private partnership project and developing bidding documents, from hiring advisors to toolkits and checklists and procurement processes. It also includes links to several tools and resources. The tools and resources are mostly targeted toward infrastructure, so they may be most useful for private entities interested in the social determinants of health rather than health outcomes directly.
Raikes Foundation | https://raikesfoundation.org/impact-driven-philanthropy | Collection of resources on impact philanthropy | This website gives an overview of impact-driven philanthropy and the Raikes Foundation approach to it. The website also provides resources for recommended readings and some illustrative grants.
Social Entrepreneurship Support Network of the Baltic Sea Region | http://www.socialenterprisebsr.net/2016/04/5-toolkits-for-social-enterprise/ | Collection of social enterprise toolkits | Produced by the Social Entrepreneurship Support Network of the Baltic Sea Region and co-financed by the European Union, these five social enterprise toolkits for social enterprise are intended to help users with feasibility studies, market assessment, financial forecasting, intellectual property rights, and payroll management for a social enterprise. Some of these toolkits include templates and downloadable Excel files to help users execute their ideas.
Teachers College, Columbia University | https://www.tc.columbia.edu/articles/2019/august/getting-low-income-families-to-higher-opportunity-neighborhoods/ | Article on housing choice vouchers (Section 8) | This article summarizes empirical research showing unprecedented gains from an intervention that reduces common barriers to using housing choice vouchers and helps move low-income families to “higher-opportunity” neighborhoods.
The Case Foundation | https://casefoundation.org/wp-content/uploads/2014/09/Short-Guide-Oct2015-Digital-FINAL.pdf | Guide to impact investing | This guide is a basic primer to help individuals better understand how business can drive social change and create social impact. It is designed to help high net worth individuals, family offices, and others to know some of the questions, if not the answers, to determine what’s right for them and what to do next to move toward meaningful, measurable impact. The guide includes a flexible framework and a simple taxonomy to help people understand impact investing.
The Democracy Collaborative | https://hospitaltoolkits.org/workforce/ | Inclusive local hiring toolkit | This inclusive local hiring toolkit is designed to help health systems establish a local and inclusive hiring strategy that allows them to invest in an ecosystem of success that lifts up local residents; helps create career pathways for low-income, minority, and hard-to-employ populations; and begins to transform neighborhoods. This toolkit includes case studies, strategies, and information on return on investment.
The Democracy Collaborative | https://hospitaltoolkits.org/investment/ | Place-based investing toolkit | This place-based investing toolkit outlines a range of strategies for how health systems are using their investment assets to help address the resource gaps that keep communities from achieving better health and well-being. The toolkit includes case studies, information to help users implement projects that may have big impacts, and resources on measuring performance and impact.

a Descriptions are used in full or adapted from content in the respective tool or resource or from content on the respective organization’s website.

Table A.7 Chapter 6: Tools and resources

Organization | Link | Type of tool or resource | Description^a^
Centers for Disease Control and Prevention | https://www.cdc.gov/workplacehealthpromotion/index.html | Tools on workplace health promotion, including the Worksite Health Scorecard to assess effectiveness of health promotion interventions, and the Workplace Health Resource Center’s compilation of tools from public, private, and nonprofit groups. | This website teaches visitors about workplace health promotion and how to design, implement, and evaluate effective workplace health programs. It includes a description of the workplace health model, a resource center, information on the Work@Health training program, and the Worksite Health Scorecard.
Centers for Disease Control and Prevention | https://www.cdc.gov/physicalactivity/walking/call-to-action/pdf/employers.pdf | Walkability resource for employers | Fact sheet from the U.S. Surgeon General offers guidance on how businesses can educate and promote worksite programs and policies that support walking and walkability.
Centers for Disease Control and Prevention and Office of the Surgeon General | https://phgkb.cdc.gov/FHH/html/index.html | Family health history collection tool | With this health history collection tool, users can enter their family health history to learn about their risk for health conditions that may run in their families. Users can print their family health history to share it with family members and healthcare providers. Family health histories can be saved so that they can be updated over time.
Employer Assistance and Resource Network on Disability Inclusion | https://askearn.org/mentalhealth/ | Mental health toolkit | This toolkit delivers background information, tools, and resources that can help employers learn more about mental health issues and cultivate a welcoming and supportive work environment for employees who may be facing mental health issues. It also presents a framework for fostering a mental health-friendly workplace, all built around the “4 A’s”: Awareness, Accommodations, Assistance, and Access.
Health Enhancement Research Organization | https://hero-health.org/hero-scorecard/ | Workplace health and well-being tool | This free, web-based tool is designed to help employers, providers, and other stakeholders identify and learn about best practices related to workplace health and well-being. The scorecard has been subjected to validation studies aligning higher scores with better health risk trends, medical cost trends, and stock performance, and a new study links specific practices to higher participation rates, health impact, cost impact, and employee perceptions of organizational support.
Intel | https://www.intel.com/content/www/us/en/big-data/building-a-data-driven-business.html | Article on building a data-driven business | This articles gives a brief overview of how to build a data-driven business and is part of a series titled, “From Data to Action.” It discusses the importance of using data to drive decisionmaking and provides some examples from Chevron and Booz-Allen Hamilton.
National Alliance on Mental Illness-New York City Metro and others | http://workplacementalhealth.org/getattachment/Making-The-Business-Case/Link-2-Title/working-well-toolkit.pdf?lang=en-US | Toolkit for leading a mentally healthy business | This toolkit provides human resource professionals and business leaders with practical information and strategies, assessment tools, mental health programs, and case studies to educate employers about current best practices to create supportive workplace environments. The goal of the toolkit is to build a strong team of working professionals who are cognizant of available support services for mental health and well-being. The toolkit is not an exhaustive list of strategies. Instead, it serves as a starting place for the journey toward eradicating mental health stigma in the workplace.
Penn Medicine | https://www.pennmedicine.org/updates/health-risk-assessment-tools | Set of health risk assessment tools | This set of risk assessments helps users compare their risks to the average person’s risks based on age and ethnicity. These tools can also be used to help users identify any risk factors they may have for a number of health conditions. Assessments cover risks for breast cancer, diabetes, and joint health, among others.
Utah Department of Health, Bureau of Health Promotion | http://choosehealth.utah.gov/documents/pdfs/ACA_Booklet.pdf | Guide on worksite wellness policy ideas and resources | This guide describes the importance of workplace wellness and offers policy ideas and examples of workplace wellness policies, tools and resources, and policy templates.
World Health Organization | https://www.who.int/mental_health/in_the_workplace/en/ | Information sheet on mental health in the workplace | This information sheet delivers a quick overview of the importance of addressing mental health in the workplace, discusses work-related risk factors for poor health, offers tips for creating a mentally healthy workplace, and includes links to other helpful resources.

a Descriptions are used in full or adapted from content in the respective tool or resource or from content on the respective organization’s website.

Table A.8 Chapter 7: Tools and resources

Organization | Link | Type of tool or resource | Description^a^
Arizona State University | https://www.azfoundation.org/Portals/0/Uploads/Documents/Centers/Pakis_Report.pdf | Report on the business case for corporate philanthropy | This study, the first of a two part study examining the business case for corporate philanthropy, identifies findings in the literature relating to the motivations for corporate philanthropy, potential benefits for implementing firms, and examples of societal impacts.
Association for Project Management | https://www.apm.org.uk/resources/find-a-resource/stakeholder-engagement/key-principles/ | Key principles of stakeholder engagement | This website serves as a gateway to a collection of resources—including case studies, patterns, tools, bibliography, presentations, and videos—on 10 principles of stakeholder engagement. Each principle has its own set of resources.
Business for Social Responsibility | https://www.bsr.org/en/our-insights/blog-view/a-guide-to-stakeholder-engagement-for-healthier-communities | Guide to stakeholder engagement for healthier communities | This brief guide includes information on stakeholder engagement and links to others tools and resources. The guide is intended to help companies manage the stakeholder engagement process more effectively and outlines three steps for companies to consider, including aligning on objectives and benefits, determining who and how to engage, and integrating learning from stakeholder engagement.
Business for Social Responsibility | https://www.bsr.org/reports/BSR_Future_of_Stakeholder_Engagement_Report.pdf | Report on the future of stakeholder engagement | This report presents a view of how companies can transform their stakeholder engagement approaches by moving from consultation of stakeholder groups toward more collaborative, inclusive, and strategic engagement. Case examples and references to relevant academic and business sources are also included.
Centers for Disease Control and Prevention | https://www.cdc.gov/globalhealth/healthprotection/fetp/training_modules/15/community-needs_pw_final_9252013.pdf | Workbook on community needs assessment | This workbook is designed to educate readers about conducting a community needs assessment.
Chartered Institute of Procurement & Supply (CIPS) | https://www.cips.org/Documents/Resources/Knowledge%20Summary/Using%20Local%20Suppliers.pdf | Resource on using local suppliers | This resource provides an overview of the benefits of using local suppliers. It also includes strategies for implementing the use of local suppliers and a practical example.
Community Planning Toolkit | https://www.communityplanningtoolkit.org/sites/default/files/Engagement.pdf | Community engagement resource and tool | This toolkit introduces readers to the concept of community engagement and educates them about a variety of issues related to improving community engagement. It also presents links to several other resources and tools.
Council on Foundations | https://www.cof.org/sites/default/files/documents/files/CorporateGuide.pdf | Guide to leading corporate philanthropy | This guide lays out an ambitious agenda to redefine the purpose and value of corporate foundations and giving programs so that they can meet the challenges of corporate citizenship. It seeks to engage the corporate philanthropy community in discussion so that it can continue to increase its impact as a significant contributor to society and enhance its value to the companies they represent.
Harvard Business School | https://www.isc.hbs.edu/creating-shared-value/csv-explained/pages/default.aspx | Website about creating shared value | This website gives a brief overview of creating shared value and describes some of its main concepts. It also provides links to resources that address how to create shared value and discuss new roles and relationships for government and nongovernmental organizations.
Institute for Local Self-Reliance | https://ilsr.org/wp-content/uploads/2018/07/ILSR_LocalPolicyGuideToolkit.pdf | Local policy action toolkit | This toolkit has several parts. The first section offers tips for independent business owners on how to engage with city officials and persuade them to adopt policies to strengthen and grow local businesses. The remainder of the toolkit consists of a two-part guide that can be shared with city officials. The first part of the guide gives an overview of why local, independent businesses matter to a city’s well-being and vitality. The second part outlines nine policies that local governments can implement to support independent businesses.
International Finance Corporation | https://www.ifc.org/wps/wcm/connect/da7fbf72-e4d9-4334-955f-671a104877a7/201911-A-guide-for-employer-supported-childcare.pdf?MOD=AJPERES&CVID=mVHadh3 | Guide for employer-sponsored childcare | This guide was developed to support employers’ implementation of childcare solutions that benefit working parents and their children. For employers who are interested, or already engaged, in the delivery of workplace childcare solutions, this guide can serve as a tool to further expand their knowledge, advance their interest, and explore multiple options, and improve their current offerings or introduce new or expand already established family-friendly benefits. It provides practical guidance on how to select and implement an employer-supported childcare program that meets the needs of employees, business, and communities.
Massachusetts Institute of Technology | https://livingwage.mit.edu/ | Living wage calculator | This living wage calculator can be used to estimate the cost of living in one’s community or region based on typical expenses. It may help individuals, communities, and employers determine a local wage rate that allows residents to meet minimum standards of living.
Santa Rosa (California) Metro Chamber | https://www.santarosametrochamber.com/clientuploads/PDF/2019/ESCC.pdf | Resource on the importance of childcare for business | This brief resource explains why childcare matters to business and offers background on the current and future workforce and why investing in childcare matters. It also describes what the Santa Rosa Metro Chamber is doing to help businesses invest in or think about investing in childcare.
The ESOP Association | https://esopassociation.org/resources | Collection of resources on employee stock ownership plans (ESOPs) | These resources are designed to expand knowledge of employee ownership, boost the ownership culture, fine tune ESOP administration, and enhance ESOPs overall.
University of Wisconsin | https://sustain.wisconsin.edu/sustainability/corporate-social-responsibility/ | Website on corporate social responsibility | This website presents a brief overview of corporate social responsibility. It also describes five reasons why corporate social responsibility is important: minimized risk; constant innovation; cost savings; investor and consumer loyalty; and happier, more productive employees.

a Descriptions are used in full or adapted from content in the respective tool or resource or from content on the respective organization’s website.