# Appendix. Supporting Tables

Table

Detailed tables with body measurements or indices from the National Health and Nutrition Examination Survey, August 2021–August 2023

Table number | Measurement unit or index | Age group (years)
1 | Weight (kilograms) | 2–19
2 | Weight (pounds) | 2–19
3 | Weight (kilograms) | 20 and older
4 | Weight (pounds) | 20 and older
5 | Standing height (centimeters) | 2–19
6 | Standing height (inches) | 2–19
7 | Standing height (centimeters) | 20 and older
8 | Standing height (inches) | 20 and older
9 | Body mass index | 2–19
10 | Body mass index | 20 and older
11 | Waist circumference (centimeters) | 2–19
12 | Waist circumference (centimeters) | 20 and older
13 | Hip circumference (centimeters) | 12–19
14 | Hip circumference (centimeters) | 20 and older
15 | Mid-upper arm circumference (centimeters) | 2–19
16 | Mid-upper arm circumference (centimeters) | 20 and older
17 | Upper arm length (centimeters) | 2–19
18 | Upper arm length (centimeters) | 20 and older
19 | Upper leg length (centimeters) | 8–19
20 | Upper leg length (centimeters) | 20 and older

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 1

Weight in kilograms for children and adolescents ages 2–19 years and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Kilograms
2–3 | 125 | 15.0 | 0.3 | 11.5 | 11.9 | 12.5 | 13.2 | 14.6 | 16.4 | 16.9 | 17.8 | 19.2
4–5 | 155 | 20.3 | 0.4 | 15.0 | 15.5 | 16.3 | 17.3 | 19.5 | 21.8 | 23.6 | 25.1 | 28.0
6–7 | 122 | 25.5 | 0.6 | 18.0 | 19.4 | 20.4 | 21.6 | 24.1 | 28.4 | 32.1 | 34.0 | 36.2
8–9 | 171 | 33.5 | 0.8 | 23.0 | 24.5 | 25.2 | 27.4 | 30.5 | 37.4 | 41.3 | 43.5 | 53.8
10–11 | 140 | 46.7 | 1.6 | 27.2 | 29.6 | 31.3 | 35.7 | 40.5 | 55.8 | 62.5 | 68.5 | †
12–13 | 143 | 58.3 | 1.6 | 37.3 | 39.6 | 42.7 | 47.1 | 55.2 | 63.0 | 75.4 | 81.1 | †
14–15 | 145 | 71.2 | 1.9 | 43.4 | 48.4 | 51.6 | 55.0 | 66.2 | 82.8 | 95.2 | 101.7 | 112.3
16–17 | 136 | 76.3 | 2.7 | 50.6 | 53.1 | 55.7 | 60.0 | 74.0 | 85.7 | 96.3 | 100.4 | †
18–19 | 138 | 77.0 | 2.0 | 51.8 | 53.9 | 56.3 | 62.6 | 72.3 | 86.3 | 95.3 | 103.1 | 110.3
Female
2–3 | 100 | 14.5 | 0.3 | 10.8 | 11.3 | 11.9 | 12.5 | 14.5 | 15.9 | 16.4 | 17.2 | 19.2
4–5 | 151 | 19.5 | 0.3 | 14.9 | 15.5 | 15.9 | 16.5 | 18.3 | 21.2 | 23.2 | 25.9 | 28.7
6–7 | 149 | 26.0 | 0.6 | 18.0 | 18.7 | 19.7 | 21.2 | 24.5 | 28.2 | 32.1 | 35.7 | 40.2
8–9 | 135 | 34.3 | 1.3 | 23.0 | 24.6 | 25.5 | 28.0 | 31.4 | 37.8 | 44.0 | 45.3 | 57.3
10–11 | 151 | 46.0 | 1.2 | 30.2 | 32.3 | 33.4 | 35.3 | 43.2 | 52.5 | 59.7 | 64.4 | 73.6
12–13 | 161 | 55.4 | 1.4 | 36.6 | 41.3 | 41.9 | 46.5 | 52.3 | 60.9 | 65.3 | 73.1 | 81.4
14–15 | 126 | 61.9 | 1.8 | 39.7 | 45.1 | 47.3 | 50.6 | 57.1 | 68.7 | 80.4 | 86.4 | 97.4
16–17 | 147 | 64.4 | 2.0 | 45.2 | 48.1 | 48.8 | 51.6 | 59.7 | 71.6 | 78.6 | 86.6 | 103.2
18–19 | 128 | 69.1 | 2.1 | 43.2 | 45.4 | 48.9 | 52.7 | 63.7 | 82.6 | 93.0 | 99.3 | 110.7

† Estimate not shown because the standard error of the 95th percentile could not be computed.

^1^Age is at time of examination.

NOTES: Data exclude pregnant females. Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 2

Weight in pounds for children and adolescents ages 2–19 years and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Pounds
2–3 | 125 | 33.1 | 0.8 | 25.4 | 26.3 | 27.6 | 29.2 | 32.2 | 36.2 | 37.3 | 39.1 | 42.4
4–5 | 155 | 44.8 | 0.9 | 33.2 | 34.3 | 35.9 | 38.1 | 43.1 | 48.0 | 52.0 | 55.4 | 61.7
6–7 | 122 | 56.2 | 1.3 | 39.7 | 42.8 | 45.0 | 47.7 | 53.1 | 62.5 | 70.7 | 74.8 | 79.8
8–9 | 171 | 73.9 | 1.7 | 50.6 | 53.9 | 55.5 | 60.4 | 67.2 | 82.4 | 91.0 | 95.9 | 118.5
10–11 | 140 | 103.0 | 3.6 | 60.0 | 65.2 | 69.0 | 78.8 | 89.2 | 123.1 | 137.8 | 151.0 | †
12–13 | 143 | 128.5 | 3.5 | 82.1 | 87.3 | 94.1 | 103.9 | 121.7 | 138.9 | 166.3 | 178.8 | †
14–15 | 145 | 156.9 | 4.2 | 95.7 | 106.7 | 113.7 | 121.3 | 145.9 | 182.5 | 210.0 | 224.2 | 247.6
16–17 | 136 | 168.3 | 5.9 | 111.6 | 117.1 | 122.8 | 132.3 | 163.1 | 189.0 | 212.2 | 221.4 | †
18–19 | 138 | 169.8 | 4.4 | 114.1 | 118.8 | 124.2 | 138.0 | 159.4 | 190.2 | 210.1 | 227.4 | 243.2
Female
2–3 | 100 | 32.0 | 0.6 | 23.8 | 25.0 | 26.3 | 27.5 | 32.1 | 35.0 | 36.2 | 38.0 | 42.3
4–5 | 151 | 43.0 | 0.8 | 32.7 | 34.1 | 35.1 | 36.4 | 40.2 | 46.7 | 51.0 | 57.2 | 63.2
6–7 | 149 | 57.4 | 1.4 | 39.8 | 41.2 | 43.5 | 46.7 | 53.9 | 62.1 | 70.8 | 78.6 | 88.7
8–9 | 135 | 75.7 | 2.8 | 50.8 | 54.2 | 56.1 | 61.7 | 69.2 | 83.4 | 97.1 | 99.9 | 126.3
10–11 | 151 | 101.4 | 2.6 | 66.6 | 71.2 | 73.6 | 77.8 | 95.2 | 115.8 | 131.5 | 142.1 | 162.2
12–13 | 161 | 122.2 | 3.1 | 80.8 | 90.9 | 92.5 | 102.6 | 115.3 | 134.3 | 143.9 | 161.2 | 179.4
14–15 | 126 | 136.5 | 3.9 | 87.5 | 99.3 | 104.2 | 111.6 | 125.8 | 151.6 | 177.2 | 190.5 | 214.7
16–17 | 147 | 141.9 | 4.4 | 99.6 | 106.0 | 107.6 | 113.7 | 131.7 | 157.8 | 173.4 | 190.8 | 227.4
18–19 | 128 | 152.3 | 4.6 | 95.1 | 100.1 | 107.9 | 116.1 | 140.5 | 182.1 | 205.1 | 218.9 | 244.0

† Estimate not shown because the standard error of the 95th percentile could not be computed.

^1^Age is at time of examination.

NOTES: Data exclude pregnant females. Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 3

Weight in kilograms for adults age 20 and older and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Kilograms
20 and older | 2,688 | 90.3 | 0.9 | 60.9 | 66.6 | 70.0 | 75.4 | 86.6 | 100.6 | 111.0 | 118.8 | 131.8
20–29 | 287 | 86.8 | 1.8 | 57.0 | 60.5 | 64.2 | 72.2 | 83.7 | 98.2 | 108.1 | 114.7 | 128.3
30–39 | 385 | 91.4 | 1.1 | 63.6 | 69.8 | 71.1 | 77.1 | 87.1 | 101.5 | 110.0 | 121.0 | 132.5
40–49 | 347 | 95.3 | 2.0 | 66.0 | 69.7 | 73.2 | 78.5 | 88.4 | 107.7 | 119.7 | 125.1 | 141.9
50–59 | 415 | 92.1 | 1.5 | 61.0 | 68.1 | 71.2 | 76.8 | 87.8 | 102.0 | 113.6 | 119.8 | 138.7
60–69 | 651 | 89.2 | 1.1 | 62.6 | 67.1 | 69.9 | 76.0 | 86.9 | 99.0 | 108.3 | 114.0 | 123.9
70–79 | 446 | 87.7 | 1.5 | 60.8 | 66.2 | 68.8 | 74.5 | 86.6 | 96.5 | 106.8 | 111.7 | 121.3
80 and older | 157 | 81.7 | 0.9 | 58.0 | 63.3 | 66.7 | 70.8 | 79.9 | 90.0 | 96.5 | 99.6 | 108.5
Female
20 and older | 3,254 | 77.9 | 0.8 | 50.7 | 54.7 | 57.8 | 62.6 | 73.5 | 89.2 | 99.9 | 107.2 | 119.2
20–29 | 337 | 74.8 | 2.1 | 47.6 | 52.9 | 54.9 | 59.4 | 68.9 | 82.9 | 98.2 | 107.3 | 121.3
30–39 | 491 | 80.9 | 0.9 | 51.4 | 55.4 | 58.9 | 63.1 | 75.0 | 93.3 | 107.9 | 114.6 | 125.9
40–49 | 442 | 80.4 | 1.4 | 52.8 | 56.0 | 58.7 | 63.9 | 74.8 | 90.6 | 101.1 | 111.5 | 123.7
50–59 | 506 | 81.6 | 0.9 | 53.1 | 57.9 | 60.2 | 65.2 | 78.5 | 95.5 | 105.0 | 111.5 | 121.4
60–69 | 810 | 77.5 | 1.0 | 51.6 | 55.5 | 58.9 | 63.3 | 74.3 | 89.9 | 98.4 | 104.5 | 109.3
70–79 | 494 | 73.8 | 0.8 | 49.8 | 54.6 | 56.8 | 62.0 | 71.7 | 82.4 | 91.4 | 96.3 | 103.5
80 and older | 174 | 67.9 | 0.8 | 46.8 | 50.6 | 52.9 | 57.9 | 65.7 | 75.2 | 83.0 | 87.3 | 94.2

NOTES: Data exclude pregnant females. Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 4

Weight in pounds for adults age 20 and older and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Pounds
20 and older | 2,688 | 199.0 | 2.0 | 134.2 | 146.8 | 154.3 | 166.3 | 191.0 | 221.9 | 244.8 | 261.8 | 290.6
20–29 | 287 | 191.3 | 4.0 | 125.6 | 133.4 | 141.6 | 159.1 | 184.5 | 216.6 | 238.3 | 252.9 | 282.9
30–39 | 385 | 201.5 | 2.5 | 140.3 | 153.8 | 156.7 | 169.9 | 192.0 | 223.8 | 242.5 | 266.8 | 292.0
40–49 | 347 | 210.1 | 4.4 | 145.4 | 153.7 | 161.3 | 173.1 | 195.0 | 237.5 | 263.8 | 275.7 | 312.8
50–59 | 415 | 203.0 | 3.3 | 134.4 | 150.1 | 157.0 | 169.3 | 193.5 | 225.0 | 250.5 | 264.1 | 305.9
60–69 | 651 | 196.7 | 2.5 | 138.0 | 148.0 | 154.2 | 167.5 | 191.7 | 218.2 | 238.7 | 251.3 | 273.2
70–79 | 446 | 193.4 | 3.2 | 134.0 | 145.8 | 151.7 | 164.3 | 190.9 | 212.8 | 235.5 | 246.3 | 267.5
80 and older | 157 | 180.1 | 2.0 | 127.9 | 139.5 | 147.0 | 156.1 | 176.2 | 198.4 | 212.7 | 219.6 | 239.2
Female
20 and older | 3,254 | 171.8 | 1.7 | 111.8 | 120.6 | 127.4 | 138.0 | 162.0 | 196.7 | 220.1 | 236.3 | 262.7
20–29 | 337 | 164.9 | 4.6 | 105.0 | 116.5 | 120.9 | 130.9 | 151.9 | 182.7 | 216.5 | 236.5 | 267.4
30–39 | 491 | 178.3 | 2.0 | 113.4 | 122.1 | 129.9 | 139.2 | 165.3 | 205.7 | 237.9 | 252.7 | 277.5
40–49 | 442 | 177.3 | 3.0 | 116.4 | 123.4 | 129.5 | 140.9 | 164.8 | 199.8 | 222.9 | 245.8 | 272.7
50–59 | 506 | 180.0 | 2.0 | 117.1 | 127.7 | 132.8 | 143.7 | 173.0 | 210.6 | 231.5 | 245.8 | 267.5
60–69 | 810 | 171.0 | 2.1 | 113.7 | 122.3 | 129.9 | 139.5 | 163.8 | 198.1 | 216.8 | 230.3 | 241.0
70–79 | 494 | 162.8 | 1.8 | 109.9 | 120.3 | 125.1 | 136.6 | 158.0 | 181.6 | 201.4 | 212.2 | 228.2
80 and older | 174 | 149.7 | 1.8 | 103.1 | 111.6 | 116.6 | 127.6 | 144.8 | 165.7 | 182.9 | 192.4 | 207.8

NOTES: Data exclude pregnant females. Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 5

Height in centimeters for children and adolescents ages 2–19 years and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group (years)^1^ | Number of examined people | Mean | Standard error ofthe mean | Percentile
Sex and age group (years)^1^ | Number of examined people | Mean | Standard error ofthe mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Centimeters
2–3 | 107 | 95.2 | 0.8 | 84.7 | 86.1 | 88.3 | 90.3 | 95.3 | 99.1 | 100.3 | 102.5 | 107.5
4–5 | 154 | 110.2 | 0.8 | 100.0 | 101.8 | 102.9 | 105.4 | 109.5 | 114.1 | 117.3 | 119.7 | 122.1
6–7 | 121 | 122.6 | 0.6 | 110.8 | 112.7 | 113.8 | 118.2 | 122.7 | 127.2 | 129.6 | 130.4 | 132.1
8–9 | 171 | 134.6 | 0.3 | 123.9 | 126.0 | 127.3 | 129.8 | 134.1 | 139.3 | 142.6 | 143.9 | 146.4
10–11 | 140 | 146.8 | 0.8 | † | 134.3 | 136.5 | 140.1 | 147.5 | 153.1 | 154.8 | 156.4 | †
12–13 | 142 | 162.0 | 1.1 | 148.3 | 150.2 | 151.7 | 154.5 | 163.0 | 168.2 | 170.8 | 172.8 | 176.6
14–15 | 144 | 171.1 | 0.7 | 157.3 | 160.9 | 162.4 | 166.0 | 171.7 | 176.4 | 178.4 | 179.7 | 182.2
16–17 | 136 | 175.0 | 0.6 | 163.2 | 166.8 | 167.9 | 169.6 | 174.4 | 179.7 | 182.6 | 186.2 | 189.6
18–19 | 138 | 175.1 | 0.7 | 161.4 | 164.6 | 165.5 | 169.0 | 174.4 | 181.2 | 184.1 | 186.0 | 187.3
Female
2–3 | 93 | 94.4 | 0.8 | 82.9 | 85.0 | 87.1 | 89.2 | 94.3 | 99.0 | 101.6 | 102.7 | 105.5
4–5 | 149 | 108.9 | 0.6 | 98.8 | 100.4 | 101.8 | 103.7 | 108.5 | 112.7 | 116.6 | 119.1 | 121.8
6–7 | 149 | 122.7 | 0.6 | 113.1 | 114.1 | 114.8 | 117.0 | 122.2 | 127.2 | 129.9 | 131.3 | 134.3
8–9 | 135 | 134.8 | 0.8 | 123.3 | 126.4 | 127.8 | 129.6 | 133.8 | 139.1 | 142.7 | 144.4 | 146.0
10–11 | 151 | 148.7 | 0.8 | 133.9 | 137.3 | 140.2 | 142.9 | 147.4 | 153.5 | 158.4 | 160.6 | 163.4
12–13 | 162 | 156.4 | 0.4 | 142.2 | 145.4 | 149.2 | 151.7 | 157.2 | 161.3 | 164.3 | 164.8 | 166.6
14–15 | 126 | 159.6 | 0.7 | 150.2 | 152.0 | 153.1 | 155.9 | 159.3 | 163.9 | 165.3 | 166.6 | 169.4
16–17 | 147 | 161.5 | 0.6 | † | 152.5 | 153.3 | 156.0 | 161.1 | 166.2 | 169.1 | 170.3 | 171.7
18–19 | 128 | 161.5 | 0.7 | 150.4 | 151.5 | 153.2 | 156.2 | 162.1 | 167.0 | 169.2 | 170.0 | 171.6

† Estimate not shown because the standard error of the 5th and 95th percentiles could not be computed.

^1^Age is at time of examination.

NOTE: Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 6

Height in inches for children and adolescents ages 2–19 years and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Inches
2–3 | 107 | 37.5 | 0.3 | 33.3 | 33.9 | 34.8 | 35.5 | 37.5 | 39.0 | 39.5 | 40.4 | 42.3
4–5 | 154 | 43.4 | 0.3 | 39.4 | 40.1 | 40.5 | 41.5 | 43.1 | 44.9 | 46.2 | 47.1 | 48.1
6–7 | 121 | 48.3 | 0.3 | 43.6 | 44.4 | 44.8 | 46.5 | 48.3 | 50.1 | 51.0 | 51.3 | 52.0
8–9 | 171 | 53.0 | 0.1 | 48.8 | 49.6 | 50.1 | 51.1 | 52.8 | 54.9 | 56.1 | 56.7 | 57.6
10–11 | 140 | 57.8 | 0.3 | † | 52.9 | 53.7 | 55.1 | 58.1 | 60.3 | 60.9 | 61.6 | †
12–13 | 142 | 63.8 | 0.4 | 58.4 | 59.1 | 59.7 | 60.8 | 64.2 | 66.2 | 67.2 | 68.0 | 69.5
14–15 | 144 | 67.4 | 0.3 | 61.9 | 63.4 | 63.9 | 65.4 | 67.6 | 69.5 | 70.2 | 70.7 | 71.7
16–17 | 136 | 68.9 | 0.2 | 64.2 | 65.7 | 66.1 | 66.8 | 68.7 | 70.8 | 71.9 | 73.3 | 74.7
18–19 | 138 | 68.9 | 0.3 | 63.6 | 64.8 | 65.1 | 66.5 | 68.7 | 71.4 | 72.5 | 73.2 | 73.7
Female
2–3 | 93 | 37.2 | 0.3 | 32.6 | 33.5 | 34.3 | 35.1 | 37.1 | 39.0 | 40.0 | 40.5 | 41.5
4–5 | 149 | 42.9 | 0.2 | 38.9 | 39.5 | 40.1 | 40.8 | 42.7 | 44.4 | 45.9 | 46.9 | 48.0
6–7 | 149 | 48.3 | 0.2 | 44.5 | 44.9 | 45.2 | 46.1 | 48.1 | 50.1 | 51.2 | 51.7 | 52.9
8–9 | 135 | 53.1 | 0.3 | 48.5 | 49.8 | 50.3 | 51.0 | 52.7 | 54.8 | 56.2 | 56.9 | 57.5
10–11 | 151 | 58.5 | 0.3 | 52.7 | 54.1 | 55.2 | 56.2 | 58.0 | 60.4 | 62.4 | 63.2 | 64.3
12–13 | 162 | 61.6 | 0.2 | 56.0 | 57.2 | 58.7 | 59.7 | 61.9 | 63.5 | 64.7 | 64.9 | 65.6
14–15 | 126 | 62.8 | 0.3 | 59.1 | 59.8 | 60.3 | 61.4 | 62.7 | 64.5 | 65.1 | 65.6 | 66.7
16–17 | 147 | 63.6 | 0.2 | † | 60.0 | 60.3 | 61.4 | 63.4 | 65.4 | 66.6 | 67.1 | 67.6
18–19 | 128 | 63.6 | 0.3 | 59.2 | 59.6 | 60.3 | 61.5 | 63.8 | 65.7 | 66.6 | 66.9 | 67.6

† Estimate not shown because the standard error of the 5th and 95th percentiles could not be computed.

^1^Age is at time of examination.

NOTE: Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 7

Height in centimeters for adults age 20 and older and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Centimeters
20 and older | 2,690 | 175.1 | 0.3 | 162.2 | 165.2 | 167.5 | 170.0 | 175.2 | 180.1 | 183.0 | 184.8 | 187.2
20–29 | 287 | 176.3 | 0.6 | 162.0 | 167.7 | 169.3 | 171.3 | 176.1 | 181.0 | 184.7 | 185.9 | 188.1
30–39 | 385 | 176.1 | 0.4 | 163.6 | 166.6 | 168.0 | 171.3 | 176.4 | 180.9 | 183.4 | 185.1 | 187.1
40–49 | 348 | 176.4 | 0.6 | 162.3 | 166.9 | 169.5 | 171.1 | 176.2 | 182.6 | 185.0 | 186.8 | 189.9
50–59 | 417 | 174.3 | 0.4 | 163.0 | 164.7 | 167.2 | 169.0 | 174.5 | 179.0 | 181.3 | 183.6 | 185.6
60–69 | 652 | 174.7 | 0.5 | 161.8 | 165.2 | 167.0 | 169.7 | 175.0 | 179.8 | 182.5 | 184.1 | 186.6
70–79 | 446 | 172.4 | 0.4 | 159.5 | 162.6 | 164.6 | 167.5 | 172.7 | 176.9 | 179.8 | 181.6 | 184.1
80 and older | 155 | 170.5 | 0.7 | 158.3 | 160.1 | 162.8 | 166.1 | 169.9 | 175.0 | 177.9 | 179.3 | †
Female
20 and older | 3,307 | 161.2 | 0.2 | 149.6 | 152.0 | 153.9 | 156.4 | 161.2 | 166.1 | 168.6 | 170.4 | 172.5
20–29 | 357 | 163.5 | 0.4 | 153.2 | 155.1 | 156.1 | 158.4 | 163.3 | 168.2 | 170.8 | 171.9 | 174.6
30–39 | 511 | 162.5 | 0.4 | 150.1 | 152.8 | 154.8 | 158.2 | 162.8 | 167.4 | 169.5 | 170.8 | 172.9
40–49 | 444 | 161.7 | 0.3 | 149.8 | 152.3 | 153.7 | 157.2 | 162.0 | 166.3 | 169.0 | 170.4 | 172.1
50–59 | 507 | 161.2 | 0.3 | 150.4 | 152.6 | 154.4 | 156.4 | 160.8 | 166.2 | 168.4 | 170.4 | 172.4
60–69 | 816 | 160.5 | 0.3 | 149.6 | 151.6 | 153.4 | 155.6 | 160.4 | 165.1 | 167.6 | 169.4 | 171.2
70–79 | 496 | 158.3 | 0.4 | 148.6 | 150.7 | 152.2 | 154.4 | 157.9 | 162.3 | 164.4 | 166.2 | 168.2
80 and older | 176 | 156.8 | 0.4 | 143.7 | 145.9 | 149.6 | 151.2 | 156.9 | 161.9 | 164.6 | 165.5 | †

† Estimate not shown because the standard error of the 95th percentile could not be computed.

NOTE: Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 8

Height in inches for adults age 20 and older and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Inches
20 and older | 2,690 | 68.9 | 0.1 | 63.9 | 65.0 | 65.9 | 66.9 | 69.0 | 70.9 | 72.1 | 72.7 | 73.7
20–29 | 287 | 69.4 | 0.2 | 63.8 | 66.0 | 66.6 | 67.5 | 69.3 | 71.2 | 72.7 | 73.2 | 74.1
30–39 | 385 | 69.3 | 0.2 | 64.4 | 65.6 | 66.1 | 67.4 | 69.5 | 71.2 | 72.2 | 72.9 | 73.7
40–49 | 348 | 69.4 | 0.3 | 63.9 | 65.7 | 66.7 | 67.4 | 69.4 | 71.9 | 72.9 | 73.5 | 74.8
50–59 | 417 | 68.6 | 0.2 | 64.2 | 64.9 | 65.8 | 66.6 | 68.7 | 70.5 | 71.4 | 72.3 | 73.1
60–69 | 652 | 68.8 | 0.2 | 63.7 | 65.0 | 65.8 | 66.8 | 68.9 | 70.8 | 71.8 | 72.5 | 73.5
70–79 | 446 | 67.9 | 0.2 | 62.8 | 64.0 | 64.8 | 66.0 | 68.0 | 69.6 | 70.8 | 71.5 | 72.5
80 and older | 155 | 67.1 | 0.3 | 62.3 | 63.0 | 64.1 | 65.4 | 66.9 | 68.9 | 70.0 | 70.6 | †
Female
20 and older | 3,307 | 63.5 | 0.1 | 58.9 | 59.8 | 60.6 | 61.6 | 63.5 | 65.4 | 66.4 | 67.1 | 67.9
20–29 | 357 | 64.4 | 0.2 | 60.3 | 61.1 | 61.4 | 62.4 | 64.3 | 66.2 | 67.2 | 67.7 | 68.7
30–39 | 511 | 64.0 | 0.1 | 59.1 | 60.2 | 60.9 | 62.3 | 64.1 | 65.9 | 66.7 | 67.2 | 68.1
40–49 | 444 | 63.7 | 0.1 | 59.0 | 60.0 | 60.5 | 61.9 | 63.8 | 65.5 | 66.5 | 67.1 | 67.7
50–59 | 507 | 63.5 | 0.1 | 59.2 | 60.1 | 60.8 | 61.6 | 63.3 | 65.4 | 66.3 | 67.1 | 67.9
60–69 | 816 | 63.2 | 0.1 | 58.9 | 59.7 | 60.4 | 61.3 | 63.1 | 65.0 | 66.0 | 66.7 | 67.4
70–79 | 496 | 62.3 | 0.1 | 58.5 | 59.3 | 59.9 | 60.8 | 62.2 | 63.9 | 64.7 | 65.4 | 66.2
80 and older | 176 | 61.7 | 0.2 | 56.6 | 57.5 | 58.9 | 59.5 | 61.8 | 63.8 | 64.8 | 65.2 | †

† Estimate not shown because the standard error of the 95th percentile could not be computed.

NOTE: Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 9

Body mass index values for children and adolescents ages 2–19 years and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Body mass index
2–3 | 107 | 16.8 | 0.2 | † | 14.6 | 15.0 | 15.5 | 16.6 | 17.5 | 18.2 | 18.6 | 19.2
4–5 | 154 | 16.6 | 0.2 | 14.0 | 14.5 | 14.7 | 15.2 | 16.0 | 17.4 | 17.9 | 18.5 | 21.8
6–7 | 121 | 16.9 | 0.3 | 13.5 | 14.1 | 14.6 | 14.8 | 16.1 | 17.7 | 20.0 | 21.0 | 22.2
8–9 | 171 | 18.3 | 0.4 | 14.0 | 14.3 | 14.8 | 15.5 | 17.2 | 19.6 | 21.9 | 23.2 | 26.8
10–11 | 140 | 21.3 | 0.7 | 15.2 | 15.4 | 16.0 | 16.7 | 19.0 | 25.0 | 26.6 | 29.6 | 33.3
12–13 | 142 | 22.1 | 0.5 | 16.1 | 16.7 | 17.3 | 18.1 | 20.3 | 24.8 | 27.5 | 28.4 | 32.8
14–15 | 144 | 24.2 | 0.6 | 16.2 | 17.0 | 18.5 | 19.5 | 21.6 | 27.6 | 32.3 | 35.0 | 38.1
16–17 | 136 | 24.9 | 0.7 | 16.9 | 17.7 | 18.1 | 20.1 | 23.7 | 27.9 | 30.5 | 33.2 | 36.0
18–19 | 138 | 25.0 | 0.7 | 17.4 | 18.7 | 19.5 | 20.4 | 23.6 | 27.9 | 32.3 | 32.7 | 36.9
Female
2–3 | 93 | 16.4 | 0.3 | † | 14.2 | 14.4 | 15.1 | 16.1 | 17.4 | 18.1 | 18.4 | 19.1
4–5 | 149 | 16.3 | 0.2 | 13.6 | 14.1 | 14.3 | 14.8 | 15.6 | 16.8 | 18.5 | 19.9 | 21.3
6–7 | 149 | 17.1 | 0.4 | 13.5 | 14.0 | 14.2 | 14.9 | 15.9 | 17.9 | 20.7 | 21.9 | 23.0
8–9 | 135 | 18.7 | 0.5 | 13.8 | 14.5 | 14.9 | 15.4 | 17.7 | 20.7 | 22.5 | 25.0 | 26.8
10–11 | 151 | 20.6 | 0.4 | 15.0 | 15.9 | 16.3 | 16.8 | 19.4 | 24.0 | 25.1 | 27.4 | 29.2
12–13 | 161 | 22.6 | 0.6 | 16.6 | 17.2 | 17.9 | 18.8 | 21.4 | 24.9 | 26.6 | 28.3 | 32.3
14–15 | 126 | 24.2 | 0.6 | † | 17.9 | 18.8 | 19.7 | 22.2 | 27.3 | 30.2 | 33.4 | 37.4
16–17 | 147 | 24.6 | 0.7 | 17.9 | 18.1 | 19.0 | 20.0 | 22.6 | 27.6 | 30.3 | 33.3 | 36.4
18–19 | 128 | 26.4 | 0.8 | 17.3 | 18.1 | 18.9 | 20.8 | 24.7 | 30.1 | 33.0 | 34.9 | 41.4

† Estimate not shown because the standard error of the 5th percentile could not be computed.

^1^Age is at time of examination.

NOTES: Data exclude pregnant females. Body mass index (BMI) is calculated as: BMI equals weight in kilograms divided by height in meters squared. Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 10

Body mass index values for adults age 20 and older and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Body mass Index
20 and older | 2,680 | 29.4 | 0.3 | 20.9 | 22.3 | 23.4 | 24.9 | 28.2 | 32.6 | 35.1 | 37.8 | 42.1
20–29 | 287 | 27.8 | 0.5 | 18.9 | 19.9 | 21.6 | 23.3 | 27.0 | 31.1 | 34.2 | 36.1 | 39.6
30–39 | 385 | 29.5 | 0.4 | 21.2 | 22.7 | 23.3 | 24.9 | 27.8 | 33.0 | 35.6 | 38.0 | 42.5
40–49 | 347 | 30.5 | 0.6 | 22.2 | 23.3 | 24.1 | 25.7 | 28.9 | 33.5 | 35.8 | 39.2 | 45.0
50–59 | 415 | 30.2 | 0.4 | 21.6 | 23.0 | 24.1 | 25.5 | 29.0 | 33.3 | 36.6 | 38.9 | 44.6
60–69 | 650 | 29.2 | 0.3 | 21.2 | 22.7 | 23.9 | 25.2 | 28.3 | 32.1 | 34.1 | 36.0 | 39.9
70–79 | 444 | 29.4 | 0.4 | 21.6 | 22.9 | 23.9 | 25.6 | 28.8 | 32.3 | 34.6 | 36.5 | 39.2
80 and older | 152 | 27.8 | 0.4 | 21.1 | 22.8 | 24.2 | 24.6 | 27.2 | 30.2 | 32.1 | 32.6 | 34.8
Female
20 and older | 3,249 | 30.0 | 0.3 | 19.7 | 21.5 | 22.4 | 24.1 | 28.3 | 34.4 | 38.4 | 40.9 | 44.9
20–29 | 336 | 28.0 | 0.7 | 18.6 | 19.9 | 21.0 | 22.2 | 25.5 | 31.6 | 36.6 | 39.7 | 45.6
30–39 | 490 | 30.5 | 0.4 | 19.7 | 21.3 | 22.3 | 24.2 | 28.6 | 35.2 | 40.4 | 42.1 | 47.4
40–49 | 441 | 30.7 | 0.6 | 19.7 | 21.9 | 23.0 | 24.6 | 28.5 | 35.1 | 38.8 | 41.0 | 45.6
50–59 | 506 | 31.4 | 0.3 | 20.8 | 22.3 | 23.4 | 24.9 | 30.0 | 36.5 | 40.2 | 42.4 | 45.9
60–69 | 810 | 30.1 | 0.4 | 20.0 | 22.0 | 23.1 | 24.8 | 28.8 | 34.5 | 37.9 | 40.0 | 42.5
70–79 | 493 | 29.5 | 0.4 | 20.7 | 22.0 | 23.2 | 24.7 | 28.0 | 33.4 | 36.5 | 38.3 | 42.2
80 and older | 173 | 27.7 | 0.4 | 19.2 | 21.1 | 22.0 | 23.6 | 26.9 | 31.3 | 33.3 | 34.7 | 36.3

NOTES: Data exclude pregnant females. Body mass index (BMI) is calculated as: BMI equals weight in kilograms divided by height in meters squared. Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 11

Waist circumference in centimeters for children and adolescents ages 2–19 years and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Centimeters
2–3 | 106 | 49.8 | 0.5 | 43.7 | 45.5 | 45.9 | 47.3 | 49.3 | 51.4 | 52.7 | 53.3 | 56.6
4–5 | 150 | 54.5 | 0.6 | 46.0 | 48.2 | 48.8 | 50.7 | 53.4 | 56.0 | 58.4 | 62.8 | 68.3
6–7 | 116 | 57.9 | 1.0 | † | 51.1 | 51.7 | 52.8 | 55.6 | 61.2 | 66.4 | 69.0 | 73.0
8–9 | 167 | 63.9 | 0.9 | 53.2 | 54.3 | 55.4 | 56.7 | 60.4 | 68.3 | 73.1 | 75.9 | 84.6
10–11 | 139 | 73.8 | 1.7 | † | 57.1 | 59.0 | 61.3 | 68.2 | 83.4 | 92.4 | 97.5 | 105.8
12–13 | 139 | 78.3 | 1.3 | 61.2 | 62.7 | 64.0 | 67.2 | 73.2 | 87.4 | 91.9 | 96.1 | †
14–15 | 139 | 83.1 | 1.5 | 63.6 | 66.9 | 68.5 | 69.6 | 77.1 | 91.8 | 105.5 | 109.9 | 116.7
16–17 | 133 | 85.3 | 2.0 | † | 67.8 | 68.8 | 73.4 | 81.3 | 93.9 | 102.2 | 109.1 | 116.7
18–19 | 134 | 87.0 | 1.9 | 68.4 | 70.4 | 71.9 | 75.5 | 81.9 | 97.3 | 103.5 | 107.3 | 115.3
Female
2–3 | 88 | 49.2 | 0.5 | 41.3 | 43.3 | 44.8 | 46.1 | 49.4 | 51.2 | 53.3 | 53.7 | 57.6
4–5 | 141 | 54.1 | 0.6 | 46.7 | 48.5 | 49.1 | 50.2 | 52.0 | 55.5 | 60.5 | 64.5 | 67.3
6–7 | 146 | 59.4 | 0.9 | 49.5 | 50.7 | 51.4 | 53.4 | 57.3 | 61.2 | 69.0 | 73.0 | 78.4
8–9 | 133 | 65.0 | 1.2 | 52.7 | 54.2 | 55.2 | 56.5 | 62.6 | 69.0 | 76.4 | 80.8 | 87.7
10–11 | 150 | 72.1 | 0.8 | 57.3 | 60.1 | 60.9 | 62.9 | 69.3 | 79.9 | 86.7 | 89.5 | 93.4
12–13 | 155 | 76.7 | 1.1 | 62.5 | 64.8 | 66.4 | 67.5 | 74.9 | 81.1 | 86.2 | 92.6 | 97.3
14–15 | 118 | 80.2 | 1.5 | † | 66.3 | 67.3 | 70.0 | 77.2 | 87.0 | 97.3 | 99.3 | 104.2
16–17 | 141 | 82.2 | 1.5 | 65.2 | 67.1 | 68.6 | 71.1 | 78.6 | 89.8 | 97.9 | 104.6 | 109.0
18–19 | 124 | 85.0 | 1.7 | 64.5 | 67.0 | 68.0 | 71.4 | 80.7 | 92.4 | 100.5 | 108.0 | 119.4

† Estimate not shown because the standard error of the 5th and 95th percentiles could not be computed.

^1^Age is at time of examination.

NOTES: Data exclude pregnant females. Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 12

Waist circumference in centimeters for adults age 20 and older and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Centimeters
20 and older | 2,605 | 103.0 | 0.7 | 79.3 | 83.5 | 86.8 | 91.4 | 100.9 | 112.3 | 119.8 | 124.3 | 133.2
20–29 | 282 | 95.1 | 1.3 | 71.3 | 75.7 | 77.9 | 82.6 | 93.4 | 106.1 | 112.6 | 117.8 | 124.4
30–39 | 378 | 101.3 | 0.9 | 80.3 | 82.6 | 85.9 | 90.0 | 98.6 | 109.9 | 118.9 | 123.1 | 130.5
40–49 | 340 | 104.7 | 1.4 | 83.7 | 86.6 | 88.3 | 92.2 | 101.5 | 114.0 | 120.7 | 127.7 | 139.6
50–59 | 407 | 106.4 | 1.0 | 83.2 | 88.2 | 90.5 | 94.2 | 104.3 | 114.8 | 123.4 | 128.4 | 137.0
60–69 | 631 | 105.4 | 0.9 | 84.2 | 87.4 | 90.2 | 95.5 | 104.5 | 113.1 | 119.5 | 123.4 | 132.2
70–79 | 429 | 107.5 | 1.1 | 84.6 | 88.6 | 92.8 | 97.3 | 106.6 | 117.1 | 122.6 | 126.5 | 131.3
80 and older | 138 | 104.1 | 1.1 | 84.5 | 89.6 | 92.8 | 95.3 | 102.6 | 111.4 | 117.0 | 120.5 | 126.0
Female
20 and older | 3,121 | 97.9 | 0.7 | 73.8 | 77.0 | 80.0 | 84.9 | 95.7 | 109.2 | 116.9 | 121.5 | 129.2
20–29 | 329 | 90.5 | 1.7 | 68.5 | 72.3 | 74.5 | 77.2 | 85.3 | 98.5 | 112.3 | 118.6 | 127.3
30–39 | 472 | 97.8 | 0.8 | 72.6 | 75.6 | 78.2 | 83.9 | 93.1 | 108.8 | 121.6 | 126.6 | 133.6
40–49 | 420 | 98.2 | 1.0 | 75.3 | 77.0 | 81.3 | 85.2 | 95.7 | 109.2 | 115.9 | 121.6 | 130.8
50–59 | 491 | 101.5 | 0.6 | 77.7 | 81.5 | 84.0 | 88.4 | 100.8 | 112.6 | 119.3 | 122.0 | 130.8
60–69 | 782 | 100.3 | 0.7 | 77.1 | 81.7 | 83.6 | 88.8 | 99.6 | 110.4 | 117.1 | 120.7 | 125.5
70–79 | 465 | 99.6 | 0.8 | 76.7 | 81.2 | 84.6 | 89.1 | 98.9 | 108.4 | 115.3 | 119.3 | 123.7
80 and older | 162 | 96.5 | 1.1 | 76.4 | 79.3 | 84.1 | 88.8 | 94.4 | 107.2 | 110.5 | 111.9 | 119.1

NOTES: Data exclude pregnant females. Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 13

Hip circumference in centimeters for children and adolescents ages 12–19 years and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Centimeters
12–13 | 131 | 90.5 | 1.0 | 74.2 | 77.4 | 80.4 | 82.8 | 89.2 | 95.3 | 101.9 | 103.9 | 112.1
14–15 | 136 | 97.0 | 1.3 | 76.9 | 81.6 | 85.1 | 87.2 | 93.6 | 104.5 | 110.9 | 118.3 | 124.5
16–17 | 132 | 99.9 | 1.5 | † | 85.5 | 87.5 | 90.6 | 99.2 | 105.5 | 109.6 | 116.9 | 121.8
18–19 | 134 | 100.1 | 1.4 | 84.1 | 85.1 | 87.9 | 90.6 | 98.2 | 107.1 | 111.8 | 114.3 | 123.5
Female
12–13 | 153 | 91.9 | 1.1 | 76.8 | 79.6 | 82.6 | 84.6 | 90.5 | 96.2 | 101.7 | 105.1 | 112.6
14–15 | 117 | 96.9 | 1.3 | † | 85.7 | 87.1 | 88.9 | 94.1 | 102.8 | 108.2 | 111.3 | 121.5
16–17 | 140 | 99.1 | 1.3 | 85.5 | 86.6 | 87.0 | 89.5 | 96.6 | 104.4 | 109.1 | 114.3 | 122.4
18–19 | 123 | 101.8 | 1.5 | 83.9 | 87.2 | 88.4 | 91.1 | 99.2 | 110.0 | 113.2 | 119.4 | 130.3

† Estimate not shown because the standard error of the 5th percentile could not be computed.

^1^Age is at time of examination.

NOTES: Data exclude pregnant females. Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 14

Hip circumference in centimeters for adults age 20 and older and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Centimeters
20 and older | 2,569 | 105.6 | 0.5 | 89.5 | 92.6 | 94.5 | 97.7 | 103.6 | 110.8 | 115.8 | 120.7 | 129.1
20–29 | 278 | 104.5 | 0.9 | 87.0 | 89.6 | 92.5 | 96.2 | 103.0 | 110.1 | 115.4 | 119.4 | 127.8
30–39 | 375 | 106.3 | 0.7 | 91.0 | 93.7 | 95.6 | 98.5 | 104.7 | 111.2 | 115.6 | 121.0 | 127.6
40–49 | 334 | 107.4 | 1.1 | 92.1 | 94.2 | 96.3 | 98.8 | 104.3 | 113.3 | 117.9 | 122.6 | 133.8
50–59 | 402 | 106.2 | 0.8 | 89.7 | 92.3 | 94.4 | 97.4 | 103.7 | 110.6 | 119.3 | 122.7 | 134.8
60–69 | 622 | 104.2 | 0.6 | 89.5 | 91.9 | 93.8 | 96.9 | 103.0 | 109.3 | 113.2 | 118.2 | 123.6
70–79 | 422 | 105.0 | 0.8 | 90.0 | 92.3 | 94.0 | 96.8 | 103.2 | 110.5 | 115.3 | 121.1 | 126.1
80 and older | 136 | 102.5 | 0.8 | 90.3 | 92.0 | 94.0 | 96.1 | 101.4 | 107.1 | 109.0 | 112.7 | 123.0
Female
20 and older | 3,098 | 109.8 | 0.5 | 89.7 | 92.9 | 95.5 | 98.6 | 106.8 | 118.1 | 126.0 | 131.5 | 138.4
20–29 | 328 | 107.0 | 1.2 | 87.1 | 91.7 | 93.4 | 96.6 | 104.4 | 113.7 | 121.1 | 127.8 | 135.7
30–39 | 466 | 111.6 | 0.7 | 91.0 | 94.0 | 96.5 | 99.9 | 108.1 | 120.0 | 129.9 | 135.2 | 142.0
40–49 | 420 | 111.1 | 0.9 | 90.3 | 94.7 | 96.5 | 99.5 | 107.4 | 120.9 | 127.2 | 130.2 | 139.7
50–59 | 490 | 111.5 | 0.8 | 90.1 | 93.5 | 96.3 | 99.6 | 108.3 | 121.3 | 128.8 | 133.6 | 139.2
60–69 | 780 | 110.1 | 0.8 | 88.9 | 92.7 | 95.4 | 99.2 | 108.0 | 119.5 | 126.2 | 131.1 | 137.3
70–79 | 460 | 108.6 | 0.7 | 89.4 | 93.1 | 95.6 | 98.7 | 106.4 | 116.1 | 123.3 | 128.3 | 134.4
80 and older | 154 | 104.7 | 0.7 | 87.7 | 91.1 | 92.8 | 96.8 | 103.1 | 112.2 | 117.0 | 119.8 | †

† Estimate not shown because the standard error of the 95th percentile could not be computed.

NOTES: Data exclude pregnant females. Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 15

Mid-upper arm circumference in centimeters for children and adolescents ages 2–19 years and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Centimeters
2–3 | 112 | 16.6 | 0.2 | 14.2 | 15.0 | 15.1 | 15.6 | 16.4 | 17.1 | 18.0 | 18.4 | 19.1
4–5 | 151 | 18.1 | 0.2 | 15.1 | 15.7 | 16.3 | 16.8 | 17.8 | 18.8 | 19.5 | 20.2 | 21.9
6–7 | 118 | 19.3 | 0.3 | † | 16.6 | 16.9 | 17.5 | 18.7 | 20.1 | 22.9 | 23.5 | 24.1
8–9 | 169 | 21.5 | 0.3 | 17.2 | 17.7 | 18.3 | 19.0 | 20.3 | 23.4 | 24.6 | 25.9 | 29.5
10–11 | 139 | 25.1 | 0.6 | 18.5 | 19.4 | 19.8 | 21.5 | 23.5 | 28.0 | 30.8 | 32.8 | 34.5
12–13 | 140 | 27.1 | 0.4 | 21.0 | 21.8 | 22.6 | 23.9 | 26.1 | 29.6 | 31.3 | 34.1 | 36.0
14–15 | 141 | 29.7 | 0.6 | 21.7 | 22.8 | 24.4 | 26.0 | 28.7 | 33.4 | 36.2 | 37.8 | 40.4
16–17 | 133 | 31.4 | 0.7 | † | 24.6 | 25.6 | 27.1 | 31.4 | 34.5 | 37.5 | 38.6 | 40.1
18–19 | 136 | 31.4 | 0.6 | 23.7 | 25.6 | 26.9 | 27.9 | 30.6 | 34.0 | 37.0 | 38.4 | 40.7
Female
2–3 | 91 | 16.6 | 0.2 | 14.2 | 14.7 | 15.0 | 15.4 | 16.3 | 17.6 | 18.0 | 18.2 | 19.0
4–5 | 147 | 17.9 | 0.2 | 15.2 | 15.7 | 16.0 | 16.5 | 17.4 | 18.3 | 19.5 | 21.8 | 22.7
6–7 | 147 | 19.8 | 0.3 | 16.3 | 16.4 | 17.0 | 17.8 | 19.1 | 21.0 | 23.0 | 23.7 | 25.7
8–9 | 135 | 22.1 | 0.5 | † | 18.2 | 18.5 | 19.4 | 21.3 | 24.0 | 25.5 | 27.5 | 29.3
10–11 | 151 | 24.7 | 0.3 | 19.1 | 20.0 | 20.5 | 21.2 | 23.8 | 27.4 | 29.1 | 30.2 | 32.4
12–13 | 158 | 26.7 | 0.5 | 20.7 | 21.5 | 22.0 | 23.2 | 25.9 | 28.7 | 31.1 | 33.2 | 35.4
14–15 | 123 | 28.3 | 0.4 | 19.7 | 22.9 | 23.5 | 25.4 | 26.8 | 30.7 | 32.7 | 35.0 | 38.5
16–17 | 143 | 29.1 | 0.5 | 23.3 | 23.7 | 24.3 | 25.5 | 27.8 | 31.6 | 33.4 | 35.8 | 39.5
18–19 | 128 | 30.4 | 0.6 | 22.3 | 23.2 | 23.9 | 25.6 | 29.8 | 33.8 | 37.5 | 38.4 | 40.6

† Estimate not shown because the standard error of the 5th percentile could not be computed.

^1^Age is at time of examination.

NOTES: Data exclude pregnant females. Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 16

Mid-upper arm circumference in centimeters for adults age 20 and older and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Centimeters
20 and older | 2,652 | 34.7 | 0.2 | 27.7 | 29.0 | 30.0 | 31.5 | 34.4 | 37.5 | 39.2 | 40.4 | 42.9
20–29 | 285 | 34.3 | 0.5 | 25.9 | 27.9 | 29.1 | 31.1 | 34.4 | 37.3 | 38.7 | 40.1 | 42.3
30–39 | 381 | 35.4 | 0.3 | 28.1 | 29.8 | 30.9 | 32.2 | 34.9 | 38.0 | 39.7 | 40.8 | 43.2
40–49 | 343 | 36.0 | 0.4 | 28.9 | 30.2 | 31.2 | 32.9 | 35.6 | 38.6 | 40.3 | 42.5 | 44.2
50–59 | 415 | 35.2 | 0.3 | 28.4 | 29.7 | 30.2 | 31.7 | 34.5 | 38.1 | 39.7 | 41.4 | 44.4
60–69 | 641 | 34.0 | 0.2 | 27.5 | 29.0 | 29.9 | 31.2 | 33.6 | 36.4 | 37.7 | 39.0 | 40.8
70–79 | 436 | 33.4 | 0.4 | 27.4 | 28.5 | 29.2 | 30.4 | 33.3 | 35.9 | 37.7 | 39.0 | 40.1
80 and older | 151 | 31.7 | 0.3 | 26.1 | 27.5 | 27.9 | 29.1 | 31.2 | 34.1 | 35.9 | 37.0 | 38.5
Female
20 and older | 3,198 | 32.9 | 0.2 | 25.1 | 26.4 | 27.2 | 28.7 | 32.1 | 36.1 | 38.9 | 40.5 | 43.6
20–29 | 333 | 31.9 | 0.5 | 24.3 | 25.3 | 26.0 | 27.6 | 30.9 | 35.1 | 37.6 | 39.8 | 43.3
30–39 | 480 | 33.9 | 0.3 | 25.6 | 26.5 | 27.2 | 29.7 | 32.6 | 37.5 | 40.9 | 43.2 | 45.9
40–49 | 436 | 33.6 | 0.5 | 25.5 | 26.8 | 27.8 | 29.2 | 32.5 | 36.6 | 39.3 | 41.2 | 43.9
50–59 | 500 | 33.8 | 0.2 | 26.4 | 27.5 | 28.5 | 29.8 | 33.1 | 37.4 | 39.4 | 41.0 | 43.7
60–69 | 801 | 32.8 | 0.3 | 25.3 | 26.7 | 27.8 | 29.0 | 32.2 | 35.9 | 38.5 | 39.9 | 42.2
70–79 | 481 | 32.1 | 0.2 | 25.1 | 26.3 | 27.0 | 28.6 | 31.6 | 35.2 | 37.3 | 38.6 | 40.6
80 and older | 167 | 29.8 | 0.3 | 22.6 | 23.7 | 25.4 | 26.6 | 29.3 | 32.8 | 34.2 | 35.2 | 37.4

NOTES: Data exclude pregnant females. Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 17

Upper arm length in centimeters for children and adolescents ages 2–19 years and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Centimeters
2–3 | 112 | 19.4 | 0.2 | 16.3 | 17.1 | 17.6 | 18.0 | 19.2 | 20.2 | 20.9 | 21.6 | 22.0
4–5 | 151 | 22.6 | 0.2 | 20.0 | 20.5 | 20.9 | 21.4 | 22.5 | 23.7 | 24.1 | 24.6 | 25.9
6–7 | 118 | 25.7 | 0.2 | 22.1 | 22.9 | 23.5 | 24.3 | 26.0 | 27.0 | 27.7 | 28.0 | 28.5
8–9 | 169 | 28.7 | 0.1 | 25.3 | 25.9 | 26.2 | 27.2 | 28.7 | 29.9 | 30.5 | 31.3 | 32.5
10–11 | 139 | 31.8 | 0.2 | 27.0 | 28.4 | 28.9 | 29.7 | 31.8 | 33.6 | 34.5 | 35.2 | 36.4
12–13 | 140 | 35.5 | 0.3 | 31.7 | 32.3 | 33.1 | 33.8 | 35.5 | 37.3 | 38.0 | 38.4 | 39.0
14–15 | 141 | 37.8 | 0.2 | 33.4 | 34.3 | 35.0 | 35.9 | 37.9 | 39.1 | 40.4 | 41.1 | 42.3
16–17 | 133 | 39.1 | 0.2 | 35.9 | 36.5 | 37.0 | 37.4 | 38.9 | 40.2 | 41.3 | 41.9 | 42.6
18–19 | 136 | 38.6 | 0.2 | 34.7 | 35.4 | 35.9 | 36.8 | 38.5 | 40.1 | 41.4 | 41.9 | 42.2
Female
2–3 | 91 | 19.3 | 0.2 | 16.5 | 16.9 | 17.0 | 18.1 | 19.2 | 20.5 | 21.1 | 21.4 | 21.8
4–5 | 147 | 22.3 | 0.2 | 19.5 | 20.1 | 20.2 | 20.8 | 22.3 | 23.7 | 24.1 | 24.6 | 25.4
6–7 | 147 | 25.7 | 0.1 | 22.9 | 23.5 | 23.9 | 24.4 | 25.5 | 26.9 | 27.7 | 27.9 | 28.4
8–9 | 135 | 28.4 | 0.3 | 25.1 | 26.0 | 26.3 | 26.9 | 28.1 | 29.6 | 30.4 | 31.3 | 32.2
10–11 | 151 | 32.3 | 0.2 | 27.8 | 29.3 | 30.1 | 30.5 | 32.0 | 33.7 | 35.1 | 35.8 | 36.0
12–13 | 158 | 34.2 | 0.2 | 30.5 | 31.3 | 31.8 | 32.6 | 34.2 | 35.6 | 36.8 | 37.1 | 37.9
14–15 | 123 | 35.0 | 0.2 | 31.5 | 32.0 | 32.4 | 34.2 | 35.0 | 36.4 | 37.1 | 37.5 | 38.0
16–17 | 143 | 35.5 | 0.3 | † | 32.7 | 33.2 | 34.0 | 35.4 | 37.0 | 37.8 | 38.3 | 39.0
18–19 | 128 | 35.4 | 0.3 | 31.6 | 32.1 | 33.2 | 33.9 | 35.4 | 36.9 | 37.3 | 37.7 | 38.6

† Estimate not shown because the standard error of the 5th percentile could not be computed.

^1^Age is at time of examination.

NOTE: Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 18

Upper arm length in centimeters for adults age 20 and older and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Centimeters
20 and older | 2,654 | 39.6 | 0.1 | 35.8 | 36.6 | 37.1 | 38.0 | 39.5 | 41.0 | 42.0 | 42.5 | 43.5
20–29 | 285 | 39.4 | 0.2 | 35.7 | 36.5 | 37.1 | 37.8 | 39.4 | 40.7 | 41.3 | 42.0 | 43.2
30–39 | 381 | 39.3 | 0.1 | 36.0 | 36.9 | 37.1 | 38.0 | 39.1 | 40.5 | 41.6 | 42.0 | 42.8
40–49 | 343 | 39.6 | 0.2 | 35.6 | 36.2 | 36.9 | 38.0 | 39.7 | 41.1 | 42.2 | 42.8 | 43.9
50–59 | 416 | 39.5 | 0.2 | 36.0 | 36.9 | 37.2 | 37.9 | 39.5 | 40.9 | 41.7 | 42.2 | 42.9
60–69 | 641 | 39.9 | 0.2 | 35.9 | 36.8 | 37.4 | 38.3 | 39.9 | 41.7 | 42.5 | 42.9 | 43.8
70–79 | 436 | 39.6 | 0.2 | 35.4 | 36.1 | 36.9 | 37.9 | 39.6 | 41.2 | 42.3 | 42.9 | 43.9
80 and older | 152 | 39.9 | 0.5 | 35.5 | 36.5 | 36.9 | 38.0 | 39.9 | 41.5 | 42.9 | 43.7 | 44.3
Female
20 and older | 3,239 | 36.2 | 0.1 | 32.4 | 33.2 | 33.8 | 34.6 | 36.1 | 37.6 | 38.4 | 39.0 | 39.8
20–29 | 352 | 36.0 | 0.2 | 32.5 | 33.3 | 33.8 | 34.6 | 35.9 | 37.3 | 38.2 | 38.9 | 39.5
30–39 | 500 | 36.3 | 0.1 | 32.3 | 33.1 | 33.6 | 34.5 | 36.4 | 37.9 | 38.6 | 39.0 | 39.9
40–49 | 437 | 36.1 | 0.2 | 32.2 | 32.9 | 33.5 | 34.6 | 36.0 | 37.6 | 38.5 | 39.1 | 39.6
50–59 | 500 | 36.2 | 0.2 | 32.2 | 33.4 | 33.9 | 34.6 | 36.0 | 37.9 | 38.5 | 39.1 | 39.9
60–69 | 800 | 36.3 | 0.1 | 32.8 | 33.3 | 33.9 | 34.6 | 36.3 | 37.7 | 38.5 | 39.0 | 39.9
70–79 | 482 | 36.1 | 0.1 | 32.5 | 33.4 | 33.8 | 34.5 | 36.1 | 37.3 | 38.0 | 38.7 | 39.8
80 and older | 168 | 36.0 | 0.2 | 32.1 | 32.7 | 33.5 | 34.5 | 36.1 | 37.2 | 37.9 | 38.4 | †

† Estimate not shown because the standard error of the 95th percentile could not be computed.

NOTE: Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 19

Upper leg length in centimeters for children and adolescents ages 8–19 years and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group (years)^1^ | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Centimeters
8–9 | 163 | 31.4 | 0.2 | 27.3 | 28.0 | 28.5 | 29.5 | 31.1 | 32.7 | 34.0 | 35.2 | 36.5
10–11 | 137 | 35.2 | 0.3 | 29.9 | 31.1 | 31.9 | 32.9 | 35.2 | 37.4 | 37.9 | 38.7 | 39.6
12–13 | 136 | 39.1 | 0.3 | 34.0 | 34.9 | 36.2 | 36.8 | 38.9 | 41.1 | 42.5 | 42.9 | 43.5
14–15 | 135 | 41.6 | 0.2 | 36.7 | 37.5 | 38.8 | 39.9 | 41.3 | 43.5 | 44.3 | 45.0 | 46.7
16–17 | 132 | 42.3 | 0.3 | 38.0 | 38.8 | 39.5 | 40.3 | 42.1 | 44.5 | 45.3 | 46.0 | 46.5
18–19 | 135 | 41.9 | 0.2 | 37.2 | 38.3 | 38.9 | 39.5 | 41.9 | 44.0 | 45.2 | 45.5 | 46.4
Female
8–9 | 129 | 31.5 | 0.3 | 27.2 | 28.3 | 28.6 | 29.4 | 31.6 | 33.0 | 33.5 | 34.7 | 35.8
10–11 | 147 | 35.2 | 0.2 | 30.9 | 32.1 | 32.7 | 33.2 | 35.0 | 36.8 | 38.0 | 38.8 | 39.3
12–13 | 156 | 37.3 | 0.2 | 32.5 | 34.6 | 35.0 | 35.5 | 37.1 | 39.0 | 40.0 | 40.7 | 41.2
14–15 | 119 | 37.9 | 0.3 | 34.4 | 35.0 | 35.7 | 36.2 | 37.2 | 39.4 | 40.3 | 40.8 | 42.5
16–17 | 139 | 37.8 | 0.3 | † | 34.8 | 35.2 | 35.9 | 37.7 | 39.9 | 40.3 | 41.0 | 42.1
18–19 | 123 | 38.3 | 0.4 | 34.6 | 35.2 | 35.4 | 36.5 | 38.0 | 39.9 | 40.7 | 41.5 | 43.0

† Estimate not shown because the standard error of the 5th percentile could not be computed.

^1^Age is at time of examination.

NOTE: Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table 20

Upper leg length in centimeters for adults age 20 and older and number of examined people, mean, standard error of the mean, and selected percentiles, by sex and age: United States, August 2021–August 2023

Sex and age group | Number of examined people | Mean | Standard error of the mean | Percentile
Sex and age group | Number of examined people | Mean | Standard error of the mean | 5th | 10th | 15th | 25th | 50th | 75th | 85th | 90th | 95th
Male | | Centimeters
20 and older | 2,559 | 41.0 | 0.2 | 35.8 | 37.1 | 38.0 | 39.1 | 41.0 | 43.1 | 44.1 | 44.8 | 45.9
20–29 | 277 | 42.3 | 0.3 | 38.1 | 39.2 | 39.6 | 40.3 | 42.0 | 44.4 | 45.1 | 45.8 | 46.4
30–39 | 374 | 41.9 | 0.2 | 37.5 | 38.5 | 39.0 | 40.0 | 41.7 | 43.8 | 44.6 | 45.0 | 46.2
40–49 | 331 | 41.3 | 0.2 | 36.0 | 37.5 | 38.5 | 39.3 | 41.4 | 43.2 | 44.0 | 44.8 | 45.9
50–59 | 397 | 40.4 | 0.2 | 35.4 | 36.5 | 37.5 | 38.4 | 40.3 | 42.2 | 43.4 | 44.1 | 45.1
60–69 | 618 | 40.4 | 0.2 | 35.0 | 36.4 | 37.2 | 38.4 | 40.5 | 42.5 | 43.3 | 44.1 | 45.1
70–79 | 425 | 39.4 | 0.1 | 34.4 | 35.5 | 36.2 | 37.3 | 39.4 | 41.2 | 42.2 | 42.9 | 43.7
80 and older | 137 | 39.4 | 0.5 | † | 35.9 | 36.2 | 37.2 | 39.7 | 41.3 | 42.1 | 43.0 | 43.7
Female
20 and older | 3,116 | 36.8 | 0.1 | 31.9 | 33.2 | 33.9 | 34.9 | 36.9 | 38.7 | 39.7 | 40.4 | 41.4
20–29 | 343 | 38.4 | 0.2 | 34.3 | 35.1 | 35.7 | 36.6 | 38.2 | 40.1 | 40.9 | 41.4 | 42.4
30–39 | 483 | 37.6 | 0.2 | 32.9 | 34.0 | 34.6 | 35.8 | 37.6 | 39.4 | 40.3 | 41.1 | 42.2
40–49 | 421 | 37.1 | 0.2 | 32.7 | 33.6 | 34.1 | 35.2 | 37.2 | 38.9 | 39.6 | 40.0 | 41.2
50–59 | 485 | 36.4 | 0.2 | 31.6 | 32.8 | 33.4 | 34.6 | 36.5 | 38.2 | 39.3 | 40.0 | 40.9
60–69 | 770 | 36.0 | 0.1 | 31.2 | 32.5 | 33.3 | 34.2 | 36.2 | 37.9 | 38.7 | 39.4 | 40.2
70–79 | 461 | 35.4 | 0.2 | 31.2 | 32.0 | 32.7 | 33.5 | 35.5 | 37.4 | 38.1 | 38.6 | 39.5
80 and older | 153 | 35.3 | 0.3 | 30.2 | 31.5 | 32.9 | 33.7 | 35.1 | 37.0 | 37.6 | 38.3 | 40.0

† Estimate not shown because the standard error of the 5th percentile could not be computed.

NOTE: Sample size is unweighted; estimates are weighted.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table I

Body measurements or indices from the National Health and Nutrition Examination Survey, by age and survey period, 1999–2000 through August 2021–August 2023

Measurement | Age | Survey period
Measurement | Age | 1999–2000 | 2001–2002 | 2003–2004 | 2005–2006 | 2007–2008 | 2009–2010 | 2011–2012 | 2013–2014 | 2015–2016 | 2017–2018 | 2019–March 2020 | August 2021–August 2023
Weight, height, and length
Weight | All ages | x | x | x | x | x | x | x | x | x | x | x | x
Standing height | 2 years and older | x | x | x | x | x | x | x | x | x | x | x | x
Recumbent length | 0–47 months | x | x | x | x | x | x | x | x | x | x | x | x
Upper arm length | 2 months and older | x | x | x | x | x | x | x | x | x | x | x | x
Upper leg length | 8 years and older | x | x | x | x | x | x | x | x | x | x | x | x
Skinfold
Subscapular skinfold | 2 months and older | x | x | x | x | x | x | … | … | … | … | … | …
Triceps skinfold | 2 months and older | x | x | x | x | x | x | … | … | … | … | … | …
Circumference and breadth
Head circumference | 0–6 months | x | x | x | x | x | x | x | x | x | x | x | x
Waist circumference | 2 years and older | x | x | x | x | x | x | x | x | x | x | x | x
Sagittal abdominal diameter | 8 years and older | … | … | … | … | … | … | x | x | x | … | … | …
Mid-arm circumference | 2 months and older | x | x | x | x | x | x | x | x | x | x | x | x
Mid-thigh circumference | 8 years and older | x | x | x | x | … | … | … | … | … | … | … | …
Maximal calf circumference | 8 years and older | x | x | x | x | … | … | … | … | … | … | … | …
Hip (buttocks) circumference | 12 years and older | … | … | … | … | … | … | … | … | … | x | x | x
Index
Body mass index | 2 years and older | x | x | x | x | x | x | x | x | x | x | x | x

… Category not applicable.

NOTE: Data for 2017–2018 and 2019–March 2020 were also released as a combined 2017–March 2020 data file.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.

Table II

Historical summary of published anthropometry reference data

Measurement or index | Survey period
Measurement or index | 1960–1962^1–3^ | 1963–1965^4^ | 1966–1970^5^ | 1971–1974^6,7^ | 1976–1980^8^ | 1988–1994^9^ | 1999–2002^10^ | 2003–2006^11^ | 2007–2010^12^ | 2011–2014^13^ | 2015–2018^14^ | August 2021–August 2023
Weight, height, and length
Weight | x | x | x | x | x | x | x | x | x | x | x | x
Standing height | x | x | x | x | x | x | x | x | x | x | x | x
Recumbent length | … | … | … | … | x | x | x | x | x | x | x | …
Sitting height | x | x | … | x | x | x | … | … | … | … | … | …
Knee height | x | x | … | … | … | x | … | … | … | … | … | …
Elbow rest height | x | … | … | … | … | … | … | … | … | … | … | …
Popliteal height | x | x | … | … | … | … | … | … | … | … | … | …
Thigh clearance height | x | x | … | … | … | … | … | … | … | … | … | …
Buttock-knee length | x | x | … | … | … | … | … | … | … | … | … | …
Buttock-popliteal length | x | x | … | … | … | … | … | … | … | … | … | …
Elbow-wrist length | … | x | … | … | … | … | … | … | … | … | … | …
Hand length | … | x | … | … | … | … | … | … | … | … | … | …
Upper arm length | … | x | … | … | … | x | x | x | x | x | x | x
Upper leg length | … | … | … | … | … | x | x | x | x | x | x | x
Foot length | … | x | … | … | … | … | … | … | … | … | … | …
Crown-rump length | … | … | … | … | x | … | … | … | … | … | … | …
Index
Body mass index^15^ | … | … | … | … | x | x | x | x | x | x | x | x
Skinfold
Subscapular skinfold | x | x | x | x | x | x | x | x | x | … | … | …
Triceps skinfold | x | x | x | x | x | x | x | x | x | … | … | …
Thigh skinfold | … | … | … | … | … | x | … | … | … | … | … | …
Suprailiac skinfold | … | … | … | … | … | x | … | … | … | … | … | …
Circumference and breadth
Head circumference | … | … | … | … | x | x | x | x | x | x | x | …
Chest circumference | x | x | … | x | x | … | … | … | … | … | … | …
Waist circumference | x | x | … | … | … | x | x | x | x | x | x | x
Sagittal abdominal diameter | | … | … | … | … | … | … | … | … | x | … | …
Mid-arm circumference | x | x | x | x | x | x | x | x | x | x | x | x
Mid-thigh circumference | … | … | … | … | … | x | x | x | … | … | … | …
Hip (buttocks) circumference | … | x | … | … | … | x | … | … | … | … | … | x
Maximal calf circumference | … | … | … | … | … | … | x | x | … | … | … | …
Chest breadth | … | x | … | … | … | … | … | … | … | … | … | …
Hand breadth | … | x | … | … | … | … | … | … | … | … | … | …
Wrist breadth | … | … | … | … | … | x | … | … | … | … | … | …
Biacromial breadth | x | … | … | … | … | x | … | … | … | … | … | …
Bi-iliac breadth | … | … | … | … | … | x | … | … | … | … | … | …
Bitrochanteric breadth | … | … | … | x | x | … | … | … | … | … | … | …
Elbow breadth | … | … | … | x | x | x | … | … | … | … | … | …
Elbow–elbow breadth | x | x | … | … | … | … | … | … | … | … | … | …
Seat breadth | x | x | … | … | … | … | … | … | … | … | … | …
Foot breadth | … | x | … | … | … | … | … | … | … | … | … | …

… Category not applicable.

^1^Stoudt HW, Damon A, McFarland R, Roberts J. Weight, height, and selected body dimensions of adults, United States, 1960–1962. Vital Health Stat 11. 1965 Jun;(8):1–44. PMID: 14338862. Available from: https://www.cdc.gov/nchs/data/series/sr_11/sr11_008.pdf.

^2^Stoudt HW, Damon A, McFarland RA, Roberts J. Skinfolds, body girths, biacromial diameter, and selected anthropometric indices of adults, United States, 1960–1962. Vital Health Stat 11. 1970 Feb;(35):1–63. 1970. PMID: 5309272. Available from: https://www.cdc.gov/nchs/data/series/sr_11/sr11_035acc.pdf.

^3^Roberts J. Weight by height and age of adults, United States, 1960–1962. Vital Health Stat 11. 1966 May;(14):1–38. PMID: 5296365. Available from: https://www.cdc.gov/nchs/data/series/sr_11/sr11_014acc.pdf.

^4^Malina RM, Hamill PVV, Lemeshow S. Selected body measurements of children 6–11 years, United States. Vital Health Stat 11. 1973 Jan;(123):1–48. PMID: 4540661. Available from: https://www.cdc.gov/nchs/data/series/sr_11/sr11_123acc.pdf.

^5^Hamill PVV, Johnston FE, Lemeshow S. Height and weight of youths 12–17 years, United States. Vital Health Stat 11. 1973 Jan;(124):1–81. PMID: 4539878s. Available from: https://www.cdc.gov/nchs/data/series/sr_11/sr11_124.pdf.

^6^Abraham S, Johnson CL, Najjar MF. Weight and height of adults 18–74 years of age: United States, 1971–74. Vital Health Stat 11. 1979 May;(211):1– 49. PMID: 473616. Available from: https://www.cdc.gov/nchs/data/series/sr_11/sr11_211.pdf.

^7^Johnson CL, Fulwood R, Abraham S, Bryner JD. Basic data on anthropometric measurements and angular measurements of the hip and knee joints for selected age groups 1–74 years of age: United States, 1971–1975. Vital Health Stat 11. 1981 Apr;(219):1–68. PMID: 15806754. Available from: https://www.cdc.gov/nchs/data/series/sr_11/sr11_219.pdf.

^8^Najjar MF, Rowland M. Anthropometric reference data and prevalence of overweight: United States, 1976–80. Vital Health Stat 11. 1987 Oct;(238):1–73.PMID: 3424692. Available from: https://www.cdc.gov/nchs/data/series/sr_11/sr11_238.pdf.

^9^McDowell MA, Fryar CD, Ogden CL. Anthropometric reference data for children and adults: United States, 1988–1994. Vital Health Stat 11. 2009 Apr;(249):1–68. PMID: 19642512. Available from: https://www.cdc.gov/nchs/data/series/sr_11/sr11_249.pdf.

^10^McDowell MA, Fryar CD, Hirsch R, Ogden CL. Anthropometric reference data for children and adults: U.S. population, 1999–2002. Adv data. 2005 July 7;(361):1–5. PMID: 16018338. Available from: https://www.cdc.gov/nchs/data/ad/ad361.pdf.

^11^McDowell MA, Fryar CD, Ogden CL, Flegal KM. Anthropometric reference data for children and adults: United States, 2003–2006. Natl Health Stat Report. 2008 Oct 22;(10):1–48. PMID: 25585443. Available from: https://www.cdc.gov/nchs/data/nhsr/nhsr010.pdf.

^12^Fryar CD, Gu Q, Ogden CL. Anthropometric reference data for children and adults: United States, 2007–2010. Vital Health Stat 11. 2012 Oct;(252):1–48. PMID: 25204692. Available from: https://www.cdc.gov/nchs/data/series/sr_11/sr11_252.pdf.

^13^Fryar CD, Gu Q, Ogden CL, Flegal KM. Anthropometric reference data for children and adults: United States, 2011–2014. Vital Health Stat 3 Anal Stud. 2016 Aug;(39):1–46. PMID: 28437242. Available from: https://www.cdc.gov/nchs/data/series/sr_03/sr03_039.pdf.

^14^Fryar CD, Carroll MD, Gu Q, Afful J, Ogden CL. Anthropometric reference data for children and adults: United States, 2015–2018.Vital Health Stat 3. 2021 Jan;(46):1–44. PMID: 33541517. Available from: https://www.cdc.gov/nchs/data/series/sr_03/sr03-046-508.pdf.

^15^Body mass index (BMI) is calculated as: BMI equals weight in kilograms divided by height in meters squared.

NOTE: Terminology for a particular measure may have changed across survey years.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey.