# Discussion

This report presents the latest anthropometric reference data for U.S. children and adults. This is the first time since NHANES III (1988–1994) that hip circumference measurements have been included in the report.

Reference data derived from anthropometric measurements are widely used. The anthropometric data collected through NHANES are used for various applications, including public health research, health and safety policy formulation, clinical practices, and product development (25–32). These measurements serve as critical references for understanding population health trends and informing interventions aimed at improving health outcomes in adults and youth.