# Results

A list of detailed tables with distributions for the various body measurements and BMI is found in the text Table. Tables 1–20 contain the sample size, mean, standard error, and selected percentiles for the different measures. Results are reported by sex and age group. For example, during August 2021–August 2023, the average man age 20 and older weighed 199 pounds (Table 4) and was 68.9 inches (just under 5 feet 9 inches) tall (Table 8). The average woman age 20 and older weighed about 172 pounds (171.8) (Table 4) and was 63.5 inches (5 feet 3.5 inches) tall (Table 8). Results from previous surveys conducted from 1960 to 2018 for most measurements have been reported (1–6,13–24). A historical summary of published body measurement reference data is available in Appendix Table II.