# Methods

NHANES, conducted by NCHS, collects data in household interviews followed by health examinations in mobile examination centers (MECs). The MECs are staffed by full-time personnel, including health technicians who perform body measurements on survey participants using a standard protocol.

Surveys were conducted on a periodic basis from 1960 to 1994. NHANES became a continuous survey in 1999 and continued through March 2020, when data collection was paused due to the COVID-19 pandemic. NHANES data collection resumed in August 2021 using a new sample design to reduce contact between interviewers and survey participants during the continuing COVID-19 pandemic. The 2-year public-use data files for August 2021–August 2023 were used for this report (7–9). During this survey period, the overall examination response rate was 25.6%.

## Sample Description

NHANES is a complex, multistage probability sample of the civilian noninstitutionalized U.S. population. The NHANES August 2021–August 2023 sample included participants of all ages (9). Due to small sample sizes for some body measurements, only those age 2 years and older are included in this report. The analytic sample for this report was based on the August 2021–August 2023 examined sample of 8,545 people age 2 years and older. Pregnant females were excluded from the tabulations of weight, body mass index (BMI), and circumference measurements.

Age for adults was categorized into 10-year age groups and age 80 and older. For participants ages 2–19 years, results were reported by 2-year age groups. This is a change from previous anthropometric reports that were based on 4 years of NHANES data and a corresponding larger sample size, with results for children and adolescents shown by single year of age.

## Body Measures

The NHANES Anthropometry Procedures Manual describes the protocol, equipment, quality control, and measurement procedures in detail (10). All NHANES participants were eligible for the anthropometry examination component, although not all age groups were eligible for all measurements. A list of body measures by age eligibility, collected by NHANES from 1999–2000 through August 2021–August 2023, is included in Appendix Table I.

Weight was measured to the nearest 0.1 kilogram using a digital floor scale.

Upper arm length was measured with a tape measure from the posterior border of the acromion process to the tip of the olecranon process; during the measurement, the upper arm length midpoint was marked. The mid-arm circumference was measured with a tape measure at the marked point. Upper arm length and mid-arm circumference were measured to the nearest 0.1 centimeter.

Standing height or stature and waist circumference were measured to the nearest 0.1 centimeter on participants. Standing height was measured with a wall-mounted stadiometer. Waist circumference was measured with a tape measure at the uppermost lateral border of the hip crest (ilium).

Upper leg length was measured on participants age 8 and older. Upper leg measurements to the nearest 0.1 centimeter were taken on seated participants; the distance from the inguinal crease to the distal end of the femur was measured. Hip circumference was measured to the nearest 0.1 centimeter on participants age 12 years and older.

Weight and standing height values were recorded automatically. The other body measurement data were recorded using computer-assisted data entry. All results were based on a single body measurement examination.

One index is reported, BMI, calculated as weight in kilograms divided by height in meters squared (kg/m^2^). BMI is often used to define obesity.

## Statistical Analysis

Unweighted sample sizes and weighted means, standard errors, and selected percentiles were estimated. Data were weighted using examination sample weights to produce national estimates. The NHANES examination sample weights incorporate the differential probabilities of selection and include adjustments for noncoverage and nonresponse. Standard errors were estimated using SUDAAN by Taylor series linearization because of the complex sample design (11).

All estimates of means and percentiles were considered statistically reliable based on not having less than 8 degrees of freedom or a relative standard error greater than 30%. Although NCHS now uses new criteria for presentation of proportions (12), similar criteria for means and percentiles have not been established. Estimates with standard errors for the percentile that could not be calculated using SUDAAN were omitted from the tables and are identified with a dagger (†).