# Introduction

Anthropometry, the science of measuring human body dimensions, serves as a key indicator of nutritional status, overall health, dietary sufficiency, and growth patterns. The National Center for Health Statistics (NCHS) provides nationally representative, in-person body measurement data collected through the National Health and Nutrition Examination Survey (NHANES), the primary source of body measurement information for the U.S. population. These measurements offer insights into the average weight, height, length, and circumferences of U.S. children, adolescents, and adults. Previous reports by NCHS have detailed anthropometric reference tables that describe the distribution of various body measurements within the U.S. population during 1988–2018 (1–6). This report presents updated anthropometric reference data collected through NHANES from August 2021 to August 2023 for age 2 years and older by sex and age.