# References

1 McDowell MA, Fryar CD, Ogden CL. Anthropometric reference data for children and adults: United States, 1988–1994. Vital Health Stat 11. 2009;(249):1–68.
2 McDowell MA, Fryar CD, Hirsch R, Ogden CL. Anthropometric reference data for children and adults: U.S. population, 1999–2002. Adv Data. 2005;(361):1–5.
3 McDowell MA, Fryar CD, Ogden CL, Flegal KM. Anthropometric reference data for children and adults: United States, 2003– 2006. National health statistics reports. 2008;(10):1–48.
4 Fryar CD, Gu Q, Ogden CL. Anthropometric reference data for children and adults: United States, 2007– 2010. Vital Health Stat 11. 2012;(252):1–48.
5 Fryar CD, Gu Q, Ogden CL, Flegal KM. Anthropometric reference data for children and adults: United States, 2011– 2014. Vital Health Stat 3. 2016;(39):1–46.
6 Fryar CD, Carroll MD, Gu Q, Afful J, Ogden CL. Anthropometric reference data for children and adults: United States, 2015– 2018. Vital Health Stat 3. 2021;(46):1–35.
7 National Center for Health Statistics. National Health and Nutrition Examination Survey, August 2021–August 2023 data documentation, codebook, and frequencies: Body measures. 2024. Available from: https://wwwn.cdc.gov/Nchs/Data/Nhanes/Public/2021/DataFiles/BMX_L.htm.
8 National Center for Health Statistics. National Health and Nutrition Examination Survey: Brief overview and analytic guidance: NHANES August 2021–August 2023 public use file release. 2024. Available from: https://wwwn.cdc.gov/nchs/nhanes/continuousnhanes/overviewbrief.aspx?Cycle=2021-2023.
9 Terry AL, Chiappa MM, McAllister J, Woodwell DA, Graber JE. Plan and operations of the National Health and Nutrition Examination Survey, August 2021–August 2023. National Center for Health Statistics. Vital Health Stat 1. 2024 May; (66):1–21. DOI: https://dx.doi.org/10.15620/cdc/151927.
10 National Center for Health Statistics. National Health and Nutrition Examination Survey (NHANES) anthropometry procedures manual. 2021 May. Available from: https://wwwn.cdc.gov/nchs/data/nhanes/public/2021/manuals/2021-Anthropometry-Procedures-Manual-508.pdf.
11 Wolter KM. Introduction to variance estimation. 2nd ed. New York: Springer; 2007.
12 Parker JD, Talih M, Malec DJ, Beresovsky V, Carroll M, Gonzalez JF Jr, et al. National Center for Health Statistics data presentation standards for proportions. Vital Health Stat 2. 2017 Aug;(175):1–22.
13 Stoudt HW, Damon A, McFarland R, Roberts J. Weight, height, and selected body dimensions of adults, United States—1960–1962. Vital Health Stat 11. 1965 Jun;(8):1–44.
14 Stoudt HW. Skinfolds, body girths, biacromial diameter, and selected anthropometric indices of adults, United States, 1960–1962. Vital Health Stat 11. 1970 Feb;(35):1–63.
15 Roberts J. Weight by height and age of adults, United States—1960–1962. Vital Health Stat 11. 1966 May;(14):1–38.
16 Malina RM, Hamill PVV, Lemeshow S. Selected body measurements of children 6–11 years, United States. Rockville, MD: Vital Health Stat 11. 1973 Jan;(123):1–48.
17 Hamill PV, Johnston FE, Lemeshow S. Height and weight of youths 12–17 years, United States. Vital Health Stat 11. 1973(124):1–81.
18 Abraham S, Johnson CL, Najjar MF. Weight and height of adults 18–74 years of age: United States, 1971–74. Vital Health Stat 11. 1979(211):1–49.
19 Johnson CL, Fulwood R, Abraham S, Bryner JD. Basic data on anthropometric measurements and angular measurements of the hip and knee joints for selected age groups 1–74 years of age. Vital Health Stat 11. 1981(219):1–68.
20 Najjar MF, Rowland M. Anthropometric reference data and prevalence of overweight, United States, 1976–80. Vital Health Stat 11. 1987(238):1–73.
21 Najjar MF, Kuczmarski RJ. Anthropometric data and prevalence of overweight for Hispanics: 1982–84. Vital Health Stat 11. 1989(239):1–106.
22 Ogden CL, Fryar CD, Carroll MD, Flegal KM. Mean body weight, height, and body mass index, United States 1960– 2002. Adv Data. 2004(347):1–17.
23 Fryar CD, Kruszon-Moran D, Gu Q, Ogden CL. Mean body weight, height, waist circumference, and body mass index among adults: United States, 1999–2000 through 2015– 2016. Natl Health Stat Report. 2018 Dec;(122):1–16.
24 Fryar CD, Kruszon-Moran D, Gu Q, Carroll M, Ogden CL. Mean body weight, height, waist circumference, and body mass index among children and adolescents: United States, 1999– 2018. National health statistics reports. 2012(160):1–23.
25 Ogden CL, Fryar CD, Martin CB, Freedman DS, Carroll MD, Gu Q, Hales CM. Trends in obesity prevalence by race and Hispanic origin—1999–2000 to 2017– 2018. JAMA. 2020 Sep 22;324(12):1208–10. DOI: 10.1001/jama.2020.14590. PMID: 32857101.
26 Emmerich SD, Fryar CD, Stierman B, Gu Q, Afful J, Ogden CL. Trends in obesity-related measures among US children, adolescents, and adults. JAMA. 2025 Mar 25;333(12):1082–4. DOI: 10.1001/jama.2024.27676. PMID: 39946125.39946125
27 Executive Office of the President. White House Task Force on Childhood Obesity: Report to the President. Solving the problem of childhood obesity. 2010.
28 Ostchega Y, Hughes JP, Prineas RJ, Zhang G, Nwankwo T, Chiappa MM. Mid-arm circumference and recommended blood pressure cuffs for children and adolescents ages between 3 and 19 years: Data from the National Health and Nutrition Examination Survey, 1999– 2010. Blood Press Monit. 2014;19(1):26–31.
29 Ostchega Y, Hughes JP, Zhang G, Nwankwo T, Chiappa MM. Mean mid-arm circumference and blood pressure cuff sizes for U.S. adults: National Health and Nutrition Examination Survey, 1999– 2010. Blood Press Monit. 2013;18(3):138–43.
30 Kuczmarski RJ, Ogden CL, Guo SS, Grummer-Strawn LM, Flegal KM, Mei Z, et al. 2000 CDC growth charts for the United States: Methods and development. Vital Health Stat 11. 2002 May;(246):1–190. PMID: 12043359. Available from: https://www.cdc.gov/nchs/data/series/sr_11/sr11_246.pdf.
31 U.S. Department of Transportation. Advisory circular: Aircraft weight and balance control. Federal Aviation Administration. 2019 May 6. Available from: https://www.faa.gov/documentLibrary/media/Advisory_Circular/AC_120-27F.pdf.
32 Department of Homeland Security. Passenger weight and inspected vessel stability requirements; Final rule. 2010 Dec 14;75(239). Available from: https://www.dco.uscg.mil/Portals/9/DCO%20Documents/5p/CG-5PC/CG-CVC/CVC1/policy/pwivsr/Passenger_Weight_and_Inspected_Vessel_Stability_Final_Rule.pdf.