# References

1 Ingram DD, Malec DJ, Makuc DM, Kruszon-Moran D, Gindi RM, Albert M, et al. National Center for Health Statistics guidelines for analysis of trends. National Center for Health Statistics. Vital Health Stat 2. 2018 Apr;(179):1–71. PMID: 29775435.
2 Kutner MH, Nachtsheim CJ, Neter J, Li W. Applied linear statistical models. 5th ed. New York: McGraw Hill Companies, Inc.; 2005.
3 Shryock HS, Siegel JS. The methods and materials of demography. New York: Academic Press; 1976.
4 Feinleib M, Zarate AO, editors. Reconsidering age adjustment procedures: Workshop proceedings. National Center for Health Statistics. Vital Health Stat 4. 1992 Oct;(29):3–83. PMID: 1280886.
5 Klein RJ, Schoenborn CA. Age adjustment using the 2000 projected U.S. population. Healthy People 2010 Stat Notes. 2001 Jan;(20):1–10. PMID: 11676466.
6 Li X, Bush MA. Approaches for performing age-adjustment in trend analysis. Proceedings of the 2019 Joint Statistical Meetings; 2019. Available from: https://ww2.amstat.org/meetings/proceedings/2019/data/assets/pdf/1199490.pdf.
7 Korn EL, Graubard BI. Analysis of health surveys. New York: John Wiley and Sons, Inc; 1999.
8 Heeringa SG, West BT, Berglund PA. Applied survey data analysis. 2nd ed. New York: Chapman and Hall/CRC; 2010.
9 National Cancer Institute. Surveillance Research Program: Variance–covariance matrix. Available from: https://surveillance.cancer.gov/help/joinpoint/setting-parameters/input-file-tab/heteroscedastic-errors-option/variance-covariance-matrix.
10 Baisden KL, Hu P. The enigma of survey data analysis: Comparison of SAS survey procedures and SUDAAN procedures. Cary, NC: SAS Institute Inc, SAS Customer Support; 2002–2003. Statistics and Data Analysis Paper: 194–31.
11 Kim HJ, Fay MP, Feuer EJ, Midthune DN. Permutation tests for joinpoint regression with applications to cancer rates. Stat Med. 2000 Feb 15;19(3):335–51. DOI: https://onlinelibrary.wiley.com/doi/10.1002/(SICI)1097-0258(20000215)19:3%3C335::AID-SIM336%3E3.0.CO;2-Z. Erratum in: Stat Med 2001 Feb 28;20(4):655. PMID: 10649300.
12 Kim J, Kim HJ. Consistent model selection in segmented line regression. J Stat Plan Inference. 2016 Mar 1;170:106–16. DOI: 10.1016/j.jspi.2015.09.008. PMID: 26858507; PMCID: PMC4742379.26858507
13 Kim HJ, Chen HS, Midthune D, Wheeler B, Buckman DW, Green D, et al. Data-driven choice of a model selection method in joinpoint regression. J Appl Stat. 2022 Apr 18;50(9):1992–2013. DOI: 10.1080/02664763.2022.2063265. PMID: 37378270; PMCID: PMC10291945.37378270
14 National Cancer Institute. Surveillance Research Program: Non-significant change in slopes. Bethesda, MD: National Institute of Health. Available from: https://surveillance.cancer.gov/help/joinpoint/tech-help/frequently-asked-questions/non-significant-change-in-slopes.
15 Irimata KE, Bastian BA, Clarke TC, Curtin SC, Badwe R, Rui P. Guidance for selecting model options in the National Cancer Institute Joinpoint Regression Software. Vital Health Stat 2. 2022 Oct;(194):1–22. DOI: 10.15620/cdc:118050.
16 Wasserstein RL, Lazar NA. The ASA statement on p-values: Context, process, and purpose. Am Stat. 2016 Jun;70(2):129–33. DOI: 10.1080/00031305.2016.1154108.
17 Wasserstein RL, Schirm AL, Lazar NA. Moving to a world beyond “ p < 0.05.” Am Stat. 2019 Mar;73(sup1):1–19. DOI: 10.1080/00031305.2019.1583913.
18 Sullivan GM, Feinn R. Using effect size—or why the P value is not enough. J Grad Med Educ. 2012 Sep;4(3):279–82. DOI: 10.4300/JGME-D-12-00156.1. PMID: 23997866; PMCID: PMC3444174.23997866
19 Blewett LA, Rivera Drew JA, King ML, Williams KCW, Chen A, Richards S, et al. IPUMS Health Surveys: National Health Interview Series (NHIS): 7.3 [dataset]. Minneapolis, MN: IPUMS, 2023. DOI: 10.18128/D070.V7.3.
20 National Cancer Institute. Surveillance Research Program: Joinpoint. Bethesda, MD: National Institute of Health. Available from: https://surveillance.cancer.gov/help/joinpoint.
21 National Cancer Institute. Surveillance Research Program: Estimated joinpoint (estimated tau) and confidence interval. Bethesda, MD: National Institute of Health. Available from: https://surveillance.cancer.gov/help/joinpoint/setting-parameters/method-and-parameters-tab/apc-aapc-tau-confidence-intervals/parametric-confidence-intervals-for-tau.
22 Rosner B. Fundamentals of biostatistics. 7th edition. Boston, MA: Brooks/Cole, Cengage Learning; 2011.
23 Cox DR. Analysis of binary data. New York: Chapman and Hall; 1970.