# Conclusion

Given that a) a proper survey-based t test will not account for the fact that the placement of the joinpoint is not known, and b) the Joinpoint software is able to locate the placement of a joinpoint without fully accounting for all components of the survey design, the “National Center for Health Statistics Guidelines for Analysis of Trends” recommends two steps when analyzing record-level data. First, use the Joinpoint software to identify the number and placement of joinpoints using aggregated data. Second, use survey analysis software to run hypothesis tests of the differences between slopes of adjacent line segments to determine whether to retain all joinpoints. While the combined use of statistical survey software and the Joinpoint software gives analysts a better understanding of the shape and trend of the data, in practice seemingly inconsistent results may occur. As discussed in this report, several possible explanations for differences exist, including differences between polynomial and piecewise regression, incorporation of survey design features, and others. The detailed examples and frequently asked questions provide analysts with potential scenarios and guidance for decision making.

In all cases, analysts should document and provide a rationale for decisions. For example, when the p value is close to the significance threshold of α equal to 0.05 (such as when the p value is greater than or equal to 0.045 and less than or equal to 0.054), and the test statistic is on the border between the acceptance and rejection regions, analysts may decide to retain a statistically nonsignificant joinpoint, or vice versa (22). Similarly, visual inspections of the data, background information about known changes, or results from the tests for nonlinearity (such as polynomial regression or linear contrasts), may inform decisions. Importantly, if the results between the two software packages differ, the language in the results section of the report should be transparent and should clearly explain why a change in the trend line appears or does not appear, and discuss reasons why the results may not be conclusive.