# Frequently Asked Questions

## Why do results from the Joinpoint software sometimes include joinpoints that are not statistically significant when the same model is evaluated with a survey package?

Inconsistencies between the Joinpoint software and survey analysis software regarding the number and placement of joinpoints are a result of 1) different testing procedures between the two software packages, 2) different methods for capturing survey design factors, and 3) differences between individual- and aggregate-level analysis. In terms of testing procedures, depending on the data structure, the Joinpoint software uses various model selection methods (such as a sequence of permutation tests or BIC) to determine both the number and placement of joinpoints. This is a more comprehensive procedure than the survey package approach of testing the difference between two slopes using a t test once a joinpoint has already been located. In terms of survey design factors, the Joinpoint software is currently limited to using only aggregated weighted estimates and either their standard errors or a variance–covariance matrix to determine the number and placement of joinpoints. It does not use record-level data or the proper design-based degrees of freedom.

## What design factors are accounted for in SUDAAN and other survey design software that are not accounted for when design-based estimates are used in the Joinpoint software?

Design factors that are accounted for in SUDAAN and other survey design software include sample weights, the full variance–covariance structure, and design-based degrees of freedom. In the Joinpoint software, sample weights are accounted for indirectly because survey design software is used to calculate the aggregated estimates and standard errors or variance–covariance matrix before data entry. However, clear differences exist between aggregate-level analysis and record-level analysis, and survey degrees of freedom cannot be specified directly or indirectly in the Joinpoint software. More complete descriptions of survey design factors are provided below and in Issue 5 of the “National Center for Health Statistics Guidelines for Analysis of Trends.”

### Sample weights

Sample weights must be used so that the estimates along the trend line are representative of the population (see section 3.5 of Korn and Graubard [7] and Chapter 7 of Heeringa et al [8]). To mitigate some of the limitations of conducting a piecewise regression analysis using aggregated data, as is used with the Joinpoint software, the “NCHS Guidelines for Analyses of Trends” recommends that point estimates and their variances be computed using record-level data and survey analysis software first, thereby incorporating the sample weights and design variables into the aggregated estimates before they are transferred into the Joinpoint software.

### The full variance–covariance structure

The full variance–covariance structure is important when estimating the variance of the slope of a trend, particularly when analyzing surveys for which some PSUs are in the sample for multiple years (for example, NHIS). When this type of year-to-year correlation is present, failure to incorporate the full variance–covariance structure of the data in a trend analysis may result in inaccurate estimates of the variance of the slope. Specifically, positive correlation between survey years or cycles leads to variance estimates that are too small, and when the variance of the slope is underestimated, test statistics tend to be overestimated. Therefore, positive correlation often leads to overestimated test statistics.

Earlier versions of the Joinpoint software were not able to incorporate the full variance–covariance matrix, but this functionality was added to version 4.9.0.0 and later updates. See Appendix II, Appendix III, and Appendix IV for guidance on how to incorporate the variance–covariance matrix into the Joinpoint software when logistic regression will be used to model a time trend using survey data.

### Degrees of freedom

For population-based NCHS surveys, the recommended nominal degrees of freedom for a hypothesis test is generally the number of PSUs minus the number of sampling strata. For aggregated data, as is used with the Joinpoint software, it is typically a function of the number of observed time points in the analysis and the number of parameters estimated. Therefore, for NCHS surveys, the number of degrees of freedom using the record-level data analysis (survey package) will be substantially larger than the number for an aggregated data analysis (the Joinpoint software).

### Note to analysts

It is hard to know in advance when these types of design issues, such as year-to-year correlation, will influence results. Rather than try to determine in advance whether the Joinpoint software results will be useful, it is best to proceed as usual and use this information to guide decisions when inconsistent results between packages are observed in terms of the number and placement of joinpoints.

## What are the benefits of using the Joinpoint software with record-level survey data, given that analysts ultimately estimate and test the slopes of the line segments corresponding to the suggested joinpoints using a survey package (such as SUDAAN)?

Identifying a joinpoint through visual examination of the trend data may be possible, but more often the timing of a change is not obvious because the change is subtle or a volatility in the observed estimates exists. As described earlier, the Joinpoint software uses model selection methods (such as a sequence of permutation tests or BIC) to determine both the number and placement of joinpoints. This is a more comprehensive procedure than the survey package approach of testing the difference between two slopes using a t test once a joinpoint has already been located. Moreover, using the Joinpoint software in addition to survey analysis software may be useful for confirming unprecedented or surprising results. For analysis of survey data, the Joinpoint software should be used to estimate the number and location of joinpoints and survey analysis software should be used to conduct hypothesis tests of the difference between the slopes of adjacent line segments once a joinpoint has been determined.

## How does SUDAAN calculate and use degrees of freedom differently compared with the Joinpoint software?

For NCHS surveys, the recommended nominal degrees of freedom for a hypothesis test is generally the number of PSUs minus the number of sampling strata. For aggregated data, as is used with the Joinpoint software, degrees of freedom is calculated as a function of the number of observed time points in the analysis and the number of parameters being estimated. For more information, see Issue 5 in the “National Center for Health Statistics Guidelines for Analysis of Trends” (1).

## What software settings in the Joinpoint software, such as different options in the “Methods and Parameters” tab, should be used for survey data?

The Joinpoint software’s documentation provides guidance on how to use the program and describes the different options, but no clear guidelines are given for choosing optimal settings (20). The choice of Joinpoint software settings when analyzing NCHS data are discussed in Issue 12 of the “National Center for Health Statistics Guidelines for Analysis of Trends” (1) and in a separate report, “Guidance for Selecting Model Options in the National Cancer Institute Joinpoint Regression Software” (15).

## Do cases exist where it may not make sense to use the Joinpoint software?

In select instances, researchers analyzing survey data for trends may choose to ignore the results observed in the Joinpoint software or forego using the Joinpoint software altogether. For example, researchers with prior subject matter expertise or knowledge of a policy change in a particular year may choose to include a joinpoint in a piecewise regression model using survey analysis software, regardless of what the Joinpoint software suggests. In other instances, it may be challenging to identify joinpoints when few time points exist. NCI recommends not using any joinpoints when a user has fewer than seven time points (Table B). Therefore, analysts may need to decide between the standard procedure of a) using Joinpoint software to identify the number and placement of joinpoints before progressing to a record-level analysis by changing the maximum number of joinpoints the Joinpoint software will look for (this is not possible with version 4.7.0.0), or b) not using the Joinpoint software.

## Similarly, if researchers are analyzing survey data, when would it make sense to ignore results given by the Joinpoint software?

Any of the reasons given earlier in the Frequently Asked Questions may also apply to this question. In addition, if, after visual inspection, the location of a joinpoint seems off by one or two time points (based on subject matter knowledge, or if the selected joinpoint does not line up with related trend lines), the suggested joinpoint may be moved if done in a principled and defendable way. One approach would be to move the joinpoint and re-test the difference between the adjacent slopes using a survey package, and then choose the joinpoint with the greatest amount of evidence based on the magnitudes of change, the confidence intervals or standard errors, and the p values. Another approach is to rely on the confidence intervals produced with the Joinpoint software for joinpoint placements (though not all design information is accounted for) (1,21).

## Should analysts build and test a piecewise regression in the Joinpoint software or survey analysis software if they observe statistically insignificant results using polynomial models or orthogonal polynomial constrasts?

While polynomial regression and orthogonal polynomial contrasts generally produce nonlinearity assessments that are similar, the degree of nonlinearity identified by these two approaches may appear to be inconsistent with the number of joinpoints identified by piecewise regression models. This inconsistency reflects differences in the forms of nonlinearity the various approaches can detect, and, at times, the greater flexibility of the piecewise regression approach to model the diverse forms that trends take, as discussed in Issue 12 of “National Center for Health Statistics Guidelines for Analysis of Trends” (1). Therefore, if the visual display (step 1) suggests that a joinpoint exists, it is recommended that analysts test a piecewise regression model using the Joinpoint software or the survey analysis software despite the insignificant polynomial tests.

## What is the benefit of checking for nonlinearity in SUDAAN or other survey analysis software before using the Joinpoint software?

Checking for nonlinearity in SUDAAN or another survey analysis software before using the Joinpoint software or the survey analysis software to build a piecewise regression model helps analysts gather a thorough understanding of the shape of the data and the options available for model building. In some cases, analysts may discover that a quadratic or other high-order polynomial may be a better fit for the data than the originally supposed piecewise regression model.