# One Answer Is Not Always Enough

In most cases, inconsistencies between the Joinpoint software and survey analysis software are attributed to differences between polynomial and piecewise regression, survey design factors (that is, sampling weights, full variance–covariance structure, and degrees of freedom), differences between software settings or packages, or changes in the common approach taken by analysts. However, situations are often complex, and inconsistencies cannot always be attributed to one easily identified solution. Sometimes inconsistent results across the packages result from a variety of factors. Example C in Appendix I demonstrates an instance where differences between polynomial and piecewise regression curves may be intersecting with age-adjustment methods to create differences between the results from SUDAAN versus the results from the Joinpoint software. Example C may also be influenced by differences between traditional BIC and the traditional t tests used to estimate changes between successive slopes. Similarly, instances may exist where differences between the results from SUDAAN versus the results from the Joinpoint software may be explained by the fact that the Joinpoint software does not account for survey design factors, as well as the fact that the Joinpoint software was explicitly created for long trend lines with many time points; or, an instance might exist where knowledge about an influential policy change helps explain the differences observed between SUDAAN and the Joinpoint software, but differences between polynomial and piecewise regression curves may also be influencing the results. The fundamental differences described in this report are intended to help analysts consider results thoroughly and move forward with the analysis in a defendable way. This does not mean that every inconsistency will be easily traced to one (and only one) of the explanations described above.