# Explanations That Are Less Common

In other instances, it may not be clear why differences are observed between the survey analysis software and the Joinpoint software. Possible explanations include too few datapoints, differences in the methods used across software packages, differences in the methods used within the same software package, deviations in the typical procedure used by analysts due to outside knowledge, or simply unusual attributes of the data.

Occasional differences in results are common when different software packages, with different defaults, different assumptions, and different processes are compared with one another, particularly if the results produced are very close to the threshold of decision making (for example, α = 0.05 for statistical significance). For example, it is common for the estimates produced by SAS PROC SURVEYMEANS in SAS to deviate slightly from comparable estimates produced by SUDAAN (10) or the R survey package. In this case, a distinction also exists between the model selection criterion used by the Joinpoint software to determine the optimal number of joinpoints and the decision-making process used when fitting a prespecified model with the survey design software, which focuses on using traditional t tests to estimate changes between successive slopes. The permutation test and BIC use the entire time series to determine the best number of joinpoints, while segment-wise testing uses only segment-specific observations.

Differences across seemingly identical models within the same statistical package are also common when different options and settings are used to build the model. For example, the Joinpoint software includes multiple model selection techniques for identifying joinpoints, including a sequence of permutation tests (11) and BIC (12,13). Because the permutation tests and BIC use different algorithms to estimate the number and location of joinpoints, they may identify different numbers of joinpoints and the joinpoints identified may be located at different time points, particularly for trends with volatility or subtle changes in trend. Specifically, the permutation test is generally considered more conservative than BIC. Therefore, the Joinpoint software is more likely to identify a joinpoint if the BIC method is used. Moreover, times occur when the Joinpoint software recommends a joinpoint even though the t test for a change in slopes (in the Joinpoint software) is statistically insignificant. In this case, the t test used to produce the p value for a change in slopes relies on asymptotic normality, while the permutation test produces an exact p value (14). The “National Center for Health Statistics Guidelines for Analysis of Trends” recommends using the permutation test for model selection if 10 or more time points are used, and BIC if fewer than 10 time points are used or if analysts use predictive margins to incorporate covariates. For more information regarding parameter selection, which options to use, and when to consider changing the defaults in the Joinpoint software, see the “National Center for Health Statistics Guidelines for Analysis of Trends” (1) and “Guidance for Selecting Model Options in the National Cancer Institute Joinpoint Regression Software” (15).

Differences across packages could also be observed in instances where prior knowledge, a change in health policy, visual inspection, or other information causes analysts to deviate from the normal processes of decision making, such as whether to pursue a piecewise regression model using SUDAAN or other survey analysis software, despite observing statistically insignificant results using the Joinpoint software. In this case, the data may not strongly reflect what the analyst knows is true based on other research, but enough of an effect may exist to be picked up by one statistical package and not another.

Identifying joinpoints can also be challenging when few time points are available. NCI recommends not using any joinpoints when a user has fewer than seven time points (Table B). In this case, analysts may rely exclusively on results from the survey analysis package.

Table B

Recommended maximum number of joinpoints based on the number of time points using Joinpoint software

Number of time points | Default maximum number of joinpoints
0–6 | 0
7–11 | 1
12–16 | 2
17–21 | 3
22–26 | 4
27–31 | 5
32–36 | 6
37 or more | 7

SOURCE: National Cancer Institute Joinpoint Help System (see reference 20 in this report).

Similarly, trends may appear inconsistent across software packages if the analyst conducts an analysis on a small subset of record-level data, such as specific sex, age, or racial-ethnic domains. In this case, large standard errors may lead to unstable estimates at one or more time points, and slight model changes across packages may appear larger than if the analyst had access to a more robust data set for that subdomain.

Finally, as stated previously, if the results produced are close to the predetermined threshold for statistical significance (such as p close to 0.05), then fluctuations between statistically significant results and statistically insignificant results are common. Differences seen across statistical packages or across models may be due to the effect being only moderately strong and ultimately indeterminate, or due to a small variance estimate relative to the beta coefficient. In these cases, other factors, such as the absolute difference in beta coefficients or the size of variance estimates relative to beta coefficients, can be considered along with the p value as evidence for or against retaining a joinpoint in a regression model (16–18).

Example D in Appendix I presents the percentage of U.S. children age 17 and younger who had a private health insurance plan at the time of interview using data from the 2007–2018 NHIS (19). In this example, the tests for quadratic and cubic trends are both statistically significant, and the Joinpoint software suggests two joinpoints (2010 and 2013). However, when the piecewise regression model suggested by the Joinpoint software is estimated using the R survey package, the change in slopes between segments two and three (at 2013) is not statistically significant. In this case, the inconsistency between steps 1–3 and step 4 (Figure 1) are likely due to differences in the model selection criterion for the BIC test (the Joinpoint software) versus the segment-wise t test (R survey package); BIC uses the entire time series, while the segment-wise testing uses only segment-specific observations. Defaulting to the R survey package, the final piecewise regression model indicates that the percentage of U.S. children age 17 and younger who had private health insurance at the time of interview decreased from 2007–2010 and then was stable from 2010–2018.