# Influential Survey Design Factors

When the results for nonlinearity with polynomial regression or orthogonal polynomial contrasts match the piecewise regression model determined using the survey analysis software but do not align with the number of joinpoints suggested by the Joinpoint software, the differences observed across packages may be explained by design factors. Design factors, including sample weights, the full variance–covariance structure, and design-based degrees of freedom, are accounted for in SUDAAN and other survey analysis software, but are not always accounted for when using design-based estimates in the Joinpoint software. Issue 5 of the “National Center for Health Statistics Guidelines for Analysis of Trends” discusses how ignoring the design factors can affect the analysis. That explanation is reiterated here, ways the Joinpoint software has been updated since the “National Center for Health Statistics Guidelines for Analysis of Trends” was published are discussed, and readers are pointed to three sources for guidance on how to use the updated Joinpoint software in conjunction with survey analysis software when a logistic model will be used to obtain final trend estimates.

Sampling weights must be used for the estimates along the trend line to be representative of the population (7,8). To mitigate some of the limitations of conducting a piecewise regression analysis using aggregated data, as is done with the Joinpoint software, it is recommended that the point estimates and their variances be computed using record-level data and survey analysis software first, before being transferred into the Joinpoint software. If sample weights are used properly, the estimate of the slope of a trend obtained using record-level survey data and the estimate obtained using aggregated survey data tend to be similar, because the estimates along the trend line are similar. However, slight differences between the two could be observed, resulting in nonidentical trend lines, because in each package analysts estimate the same trend line using slightly different estimators. This scenario is illustrated in depth in Appendix I of the “National Center for Health Statistics Guidelines for Analysis of Trends” (1).

The full variance–covariance structure is important when estimating the variance of the slope of a trend, particularly when analyzing surveys for which some primary sampling units (PSUs) are in the sample for multiple years (for example, NHIS). When this type of year-to-year correlation is present, failure to incorporate the full variance–covariance structure of the data in a trend analysis can result in incorrect estimates of the variance of the slope. When the variance of the slope is underestimated, test statistics tend to be overestimated, which can result in an analyst concluding that a model or change in slopes is statistically significant, when in fact the low p value is simply an artifact of an underestimated variance of the slope. Early versions of the Joinpoint software were not able to incorporate the full variance–covariance structure of survey (or nonsurvey) data. For analyses conducted using these versions, instances where the Joinpoint software suggests a joinpoint but survey analysis software does not may be attributable to the variance–covariance matrix, particularly if the p value is very close to the 0.05 (or otherwise defined) threshold. Now analysts can incorporate the variance–covariance matrix by using Joinpoint software version 4.9.0.0 or later. Instructions on how to do this are provided in the NCI Joinpoint Regression Software Help System on the NCI website (9).

As pointed out by the “National Center for Health Statistics Guidelines for Analysis of Trends,” if the Joinpoint software is used to identify joinpoints and a logistic model is used to obtain final estimates of trends, the proportions (or predictive margins if the trend model includes covariates) and their standard errors should be transformed to the log-odds scale before inputting them into the Joinpoint software (1). Because the “National Center for Health Statistics Guidelines for Analysis of Trends” was published before Joinpoint software version 4.9.0.0 was released, the report does not provide information on how to transform the variance–covariance matrix to the log-odds scale. Appendix II in this report outlines how to transform the original variance–covariance matrix for a series of n estimated proportions p^_i_ , p^_i + 1_ , ... , p^_i + ( n − 1 )_ collected at time points i through { i + ( n − 1 ) } into a variance–covariance matrix for

ln ((p^_1_)/(1 − p^_1_)) , ln ((p^_2_)/(1 − p^_2_)) , ... , ln ((p^_i + ( n − 1 )_)/(1 − p^_i + ( n − 1 )_)) [ l o g - o d d s s c a l e ] The summation over i from 1 to n of r sub i multiplied by the quantity p sub i divided by p; P equals the summation over i from 1 to n of p sub i; The natural log of the quantity p hat sub 1 divided by 1 minus p hat sub 1, the natural log of the quantity p hat sub 2 divided by 1 minus p hat sub 2, and so forth, to the natural log of the quantity p hat sub i plus n minus 1 divided by 1 minus p hat sub i plus n minus 1.

Appendix III provides guidance on how to implement this transformation using SUDAAN, SAS/STAT survey procedures, and SAS PROC IML. The steps outlined in Appendix III can be generalized for use in any survey analysis software. Appendix IV provides an example showing the transformation using data from the 2007–2018 NHIS, Family Core component.

Surveys that do not visit the same location during each collection year or survey cycle sometimes assume independence of PSUs and strata across time. In this case, no overlap in PSU and strata variables across time exists, and, therefore, the covariance terms in the variance–covariance matrix associated with estimates across time are zero. This is the case for public-use NHANES data files, for example, and can be checked in any data set by producing cross-tabulations of the design variables over time.

Finally, for NCHS surveys, the recommended number of degrees of freedom for a hypothesis test is generally the number of PSUs minus the number of sampling strata. For aggregated data, as is used with the Joinpoint software, the number of degrees of freedom is typically a function of the number of observed time points in the analysis and the number of parameters estimated. Therefore, for NCHS surveys, the number of degrees of freedom using the record-level data analysis (survey package) will be substantially larger than the number for an aggregated data analysis (the Joinpoint software). Differences in the number of degrees of freedom can easily influence test statistics and p values, consequently influencing if an analyst concludes that a result is statistically significant or not.