# Age-adjustment Methods

Age adjustment is a technique used to adjust for the changing age structure in study populations by calibrating to a standard population so that all the time periods’ populations have the same age structure as the standard population. When health indicators are related to age, changes in the underlying age structure of the study population may confound differences observed in the indicator over time. Basic age adjustments help minimize these effects (3–5).

The descriptive procedures in survey analysis software, such as SUDAAN and others, use a direct age adjustment performed by applying age-specific rates in a population of interest to a standardized age distribution. For example, age-adjusted rates calculated by the direct method are:

∑_i_^n^ r_i_ ( (p_i_)/(P) )

where

r_i _= rate in age group i in the population of interest,

p_i _= standard population in age group i,

P = ∑_i_^n^ p_i_

and n = total number of age groups over the age range of the age-adjusted rate.

Consequently, aggregate estimates that are read into the Joinpoint software have been estimated using a direct age adjustment. However, SUDAAN and other survey analysis software have no available techniques for incorporating direct age adjustment into commonly used inferential procedures for record-level data, such as SUDAAN PROC REGRESS. Therefore, for trend analyses of survey data, the final estimated model using record-level data and survey analysis software must incorporate alternative age-adjustment methods, namely 1) age adjustment of survey sample weights, or 2) using age as a covariate in the final regression models (6). Subtle differences between the direct method used to produce aggregated estimates for the Joinpoint software and the alternative methods used to estimate the final piecewise model using the survey analysis software could cause apparent differences between the Joinpoint software and the survey analysis software. The “National Center for Health Statistics Guidelines for Analysis of Trends” recommends the first approach, age adjustment of survey sample weights, when fitting the final piecewise model using the survey analysis software (1).

In Example C, Appendix I, the final piecewise regression model is estimated using age-adjusted survey sample weights as recommended by the “National Center for Health Statistics Guidelines for Analysis of Trends.” However, if age-adjusted sample weights are used throughout this example for the sake of consistency between the survey analysis software and the Joinpoint software, instead of using a direct age adjustment in step 1 (Figure 1) (as recommended by the “National Center for Health Statistics Guidelines for Analysis of Trends”), conclusions and results are similar with a placement of the joinpoint at 2011–2012 instead of 2009–2010 (results not shown).