# Polynomial Versus Piecewise Regression: Similarities and Differences

“National Center for Health Statistics Guidelines for Analysis of Trends” recommends that, before using the Joinpoint software or fitting a piecewise regression model using a survey package, the data be screened for nonlinearity by performing a polynomial regression or testing the statistical significance of orthogonal polynomial contrasts. This screening is used to help determine whether piecewise regression models should be considered. While the screening is informative, polynomial regression and piecewise regression are different models. The Joinpoint software does not fit polynomial regression models or test orthogonal polynomial contrasts. Therefore, in some cases, differences between the results observed using survey analysis software and the results observed using the Joinpoint software are explained by differences in the basic characteristics of polynomial versus piecewise regression models. Specifically, this could occur if the Joinpoint software finds a joinpoint and the estimated piecewise regression model using the survey package indicates statistically significant changes in slope, but the polynomial regression terms or orthogonal polynomial contrasts used to screen for nonlinearity are not statistically significant. Similarly, screening for nonlinearity may produce statistically significant polynomial regression terms or orthogonal polynomial contrasts, but subsequent analyses using the Joinpoint software to identify joinpoints and survey analysis software to build piecewise regression models may suggest that only the linear model is statistically significant.

While both polynomial regression and piecewise regression techniques model nonlinear variations of the basic linear regression model, they are distinct models, characterizing distinct shapes. In the case of a trend analysis, a second-order polynomial regression model (quadratic) models a broad curve across time, a third-order polynomial regression model (cubic) models two broad curves across time, a fourth-order polynomial regression model (quartic) models three broad curves across time, etc. In contrast, piecewise regression models, as identified by the Joinpoint software, model trends in which a change in slope occurs at one (or more) point(s) in time. Of course, depending on the shape of the data, large differences between polynomial regression and piecewise regression models may not exist, and it may not always be clear which model offers a better fit, particularly as the order of the polynomial regression model increases. Furthermore, piecewise regression models are often preferred because they are easier to interpret than polynomial regression models and provide greater flexibility in modeling the diverse forms that trends can take.

Similarly, polynomial regression models generally align with comparisons of orthogonal polynomial contrasts. However, as polynomial regression is distinct from piecewise regression, polynomial regression is distinct from orthogonal polynomial contrasts. Regression models postulate that a probability distribution of the outcome variable exists for each level of a predictor variable, and that the means of these probability distributions vary in a systematic fashion as the values of the predictor variables change. Contrasts compare factor level means, which may or may not include multiple levels of predictor variables and are driven by pairwise comparisons. Often orthogonal polynomial contrasts are designed to mimic the polynomial regression, but they are not always identical (2).

Example C in Appendix I presents age-adjusted estimates of body mass index (BMI) in Mexican-American women from the 1999–2016 NHANES. In this example, higher-order polynomial terms are not statistically significant when estimated in SUDAAN, the Joinpoint software suggests a joinpoint at the 2009–2010 survey cycle, and a piecewise regression in SUDAAN using the model identified by the Joinpoint software indicates that the change in the slopes of the two segments around the 2009–2010 time point is statistically significant. In this case, the inconsistency between step 2 and steps 3 and 4 (Figure 1) is likely due to differences between modeling a nonlinear polynomial (quadratic) curve and modeling two linear line segments in a piecewise regression model. As explained in subsequent sections, it could also be influenced by differences between the Bayesian Information Criterion (BIC) used by the Joinpoint software and the traditional t tests used to estimate changes between successive slopes in SUDAAN. The final piecewise regression model from step 4 (Figure 1) indicates that the age-adjusted mean BMI in Mexican-American women increased at an average rate of 0.18 per survey cycle (about 0.09 per year) between 1999–2000 and 2009–2010 and at an average rate of 0.65 (about 0.32 per year) per survey cycle between 2009–2010 and 2017–2018.