# Consistent Results

Ideally, results produced by the Joinpoint software are congruent with the results produced by the survey analysis software; that is, the number and location of joinpoints identified by the Joinpoint software match the number and location of statistically significant joinpoint coefficients estimated by the survey analysis software in the prespecified segmented regression model. Naturally, because the Joinpoint software fits models based on aggregate-level estimates and survey analysis software fits models based on record-level data, this occurs when aggregate-level models and record-level models both identify the same number of statistically significant joinpoints. This section provides two examples where the results between the two software programs (or two models) are consistent.

Example A in Appendix I presents the trendline by 2-year survey cycle for elevated blood lead levels (greater than or equal to 5 μg/dL) in children ages 1–11 from the 1999–2016 NHANES. In this example, the logistic regression using SUDAAN is statistically significant, higher-order terms are not statistically significant using SUDAAN, and the Joinpoint software also suggests a linear trend with no joinpoints. Therefore, results are consistent across software programs in terms of the number of statistically significant joinpoints in the final model.

Example B in Appendix I presents yearly employment rates from the 1999–2017 CPS-ASEC collected by the U.S. Census Bureau. The employment rate represents people age 16 and older in the U.S. labor force who are employed. The labor force is defined as people who have a job and people who are jobless, looking for a job, and available for work. In this example, both the quadratic and cubic regressions are statistically significant using SAS PROC SURVEYREG, the Joinpoint software identifies joinpoints at 2002, 2006, and 2009, and the piecewise regression model identified with the Joinpoint software with joinpoints at 2002, 2006, and 2009 displays statistically significant changes in slope between all adjacent slope estimates when estimated using SAS PROC SURVEYREG. A statistically significant decline was seen from 1999 to 2002 (96% to 94%), a statistically significant increase from 2002 to 2006 (94% to 95%), a statistically significant decline from 2006 to 2009 (95% to 90%), and a statistically significant increase from 2009 to 2017 (90% to 96%). These results are consistent across software programs.