# Potential Differences

Figure 1 presents the general approach suggested by the “National Center for Health Statistics Guidelines for Analysis of Trends” when using record-level data to conduct trend analyses of survey data. This approach uses survey analysis software such as SUDAAN, the R survey package, STATA, or SAS/STAT survey procedures to compute estimates and assess nonlinearity of record-level data (steps 1, 2, and 4) and evaluates the number and location of joinpoints using the Joinpoint software (step 3).

Figure 1 General approach for conducting trend analyses of record-level survey data

NOTE: Approach suggested by “NCHS Guidelines for Analysis of Trends.”

SOURCE: National Center for Health Statistics

Figure 1 is a flow chart of the general approach for conducting trend analyses of record-level survey data.

In some cases, analysts may observe different results based on the survey analysis software compared with the Joinpoint software. This means that the model indicated in Figure 1, step 3 may differ from the model indicated in Figure 1, steps 1 and 2 or from the model indicated in Figure 1, step 4. For example, the joinpoints identified by the Joinpoint software (step 3) may not be statistically significant when the prespecified model is estimated in the survey analysis software (step 4). Many plausible explanations for these inconsistencies exist, and some are worked through in the following sections. Differences that may be observed in the magnitude of the point estimates or standard errors are not discussed because Issue 12 in the “National Center for Health Statistics Guidelines for Analysis of Trends” recommends using the Joinpoint software to estimate the number and location of the joinpoints, not to obtain slope or variance estimates for analysis of survey data (1).

Figure 2 and Table A identify instances in the analysis process where analysts may observe inconsistencies between the survey analysis software and the Joinpoint software. The two diagrams also point readers to potential explanations for these inconsistencies, which are described in subsequent sections. The remainder of the report is divided into six main sections:

Figure 2 Decision flow chart for analyzing trends of survey data for all possible scenarios

^1^Example B. Employment rate in the United States of America (1999–2017 Current Population Survey Annual Social and Economic Supplement).

^2^Example D. Private health insurance coverage in children (2007–2018 National Health Interview Survey).

^3^Example C. Age-adjusted body mass index (BMI) in Mexican-American women (1999–2016 National Health and Nutrition Examination Survey [NHANES]).

^4^Example A. Elevated blood lead levels in children (1999–2016 NHANES).

SOURCE: National Center for Health Statistics.

Figure 2 is a decision flow chart for analyzing trends of survey data for all possible scenarios.

Table A

Analyzing trends of survey data: An explanation for all possible scenarios

Possible scenarios | Polynomial statistically significant | | Polynomial not statistically significant
Possible scenarios | Joinpoint software finds a joinpoint | Joinpoint software does not find a joinpoint | Joinpoint software finds a joinpoint | Joinpoint software does not find a joinpoint
Piecewise regression statistically significant based on survey analysis software | Consistent Example B, Appendix I Employment rate in the United States of America (1999–2017 Current Population Survey Annual Social and Economic Supplement) | Potentially explained by influential survey design factors such as sample weights, the full variance-covariance structure, and degrees of freedom | Potentially explained by differences between testing for curvature or contrasts and testing for joinpointsExample C, Appendix IAge-adjusted body mass index (BMI) in Mexican-American women (1999–2016 NHANES) | Differences across age-adjustment techniques or other explanationsUnlikely outcome because the estimated piecewise regression model using the survey analysis software is typically prespecified by Joinpoint software
Piecewise regression not statistically significant based on survey analysis software | Differences across age-adjustment techniques or other explanationsExample D, Appendix IPrivate health insurance coverage in children (2007–2018 National Health Interview Survey) | Potentially explained by differences between testing for curvature or contrasts and testing for joinpoints | Potentially explained by influential survey design factors including sample weights, the full variance-covariance structure, and degrees of freedom | Consistent Example A, Appendix I Elevated blood lead levels in children (1999–2016 NHANES)

NOTE: NHANES is National Health and Nutrition Examination Survey.

SOURCE: National Center for Health Statistics, 2025.

1. In “Consistent Results,” two ideal examples which demonstrate no apparent inconsistencies are presented; one example has multiple joinpoints and one does not have any.
2. In “Polynomial Versus Piecewise Regression: Similarities and Differences,” polynomial regression models and piecewise regression models are compared because differences between the two types of models sometimes contribute to differences between the results observed in steps 2 and 3 (Figure 1) of the analysis process.
3. In “Age-adjustment methods,” brief descriptions of direct age adjustments (recommended by the “National Center for Health Statistics Guidelines for Analysis of Trends” for steps 2 and 3 of Figure 1) and alternative age-adjustment methods (recommended for step 4 of Figure 1) are presented with an explanation of when and why both methods are useful.
4. In “Influential Survey Design Factors,” factors such as survey weights, variance–covariance matrices, and design-based degrees of freedom, which are handled differently by the survey analysis software (using record-level analysis) versus the Joinpoint software (using aggregate-level analysis) are discussed. Additionally, updates to the way NCI Joinpoint software incorporates variance–covariance matrices are presented.
5. In “Explanations That Are Less Common,” other plausible explanations for the differences observed between the survey analysis software and the Joinpoint software are presented. These include too few datapoints, differences in the methods used across software packages, differences in the methods used within the same software package, deviations in the typical procedure used by analysts due to outside knowledge, and unusual attributes of the data.
6. In “One Answer Is Not Always Enough,” the intersection of the explanations described in previous sections is discussed.
7. The final section, “Frequently Asked Questions,” provides responses to frequently asked questions.

Worked examples are incorporated into the sections with details presented in Appendix I. All examples follow the approach suggested in “National Center for Health Statistics Guidelines for Analysis of Trends” and outlined in Figure 1.