# Introduction

“National Center for Health Statistics Guidelines for Analysis of Trends” (1) generally recommends the use of record-level data and survey analysis software (such as SUDAAN, the R survey package, STATA, or SAS/STAT survey procedures) when fitting trend models of survey data. However, when trends are assessed using joinpoint (that is, piecewise, segmented, or broken stick) regression models, the guidelines recommend that analysts use the most recent version of the National Cancer Institute (NCI) Joinpoint Regression Software with aggregated data to identify the number and location of joinpoints, but that survey analysis software with record-level data be used to obtain final slope estimates and to conduct tests of hypothesis for the model identified by the Joinpoint software.

In practice, some analysts have observed conflicting results between the Joinpoint software and survey analysis software. Specifically, sometimes differences in statistical significance exist between polynomial regression (survey analysis software), polynomial contrasts (survey analysis software), and piecewise regression (Joinpoint software and survey analysis software). Other times, differences exist between the number of joinpoints identified by the Joinpoint software and the number of joinpoints estimated to be statistically significant by the survey analysis software in the prespecified segmented regression model. For example, the Joinpoint software may identify two joinpoints in a trendline, while the survey analysis software only estimates that one is statistically significant. This could happen because the Joinpoint software performs aggregate-level analysis and the survey analysis software performs record-level analysis. However, it could also be due to other reasons. Easily identifying the cause of apparent differences may not be possible without studying the features of both programs in depth.

This report identifies cases where these apparent inconsistencies could occur, discusses plausible explanations for the apparent differences, and provides examples from the National Health and Nutrition Examination Survey (NHANES), the National Health Interview Survey (NHIS), and the Current Population Survey Annual Social and Economic Supplement (CPS-ASEC) to help demonstrate and discuss apparent differences. Discussion includes differences between aggregate-level analysis and record-level analysis, between polynomial and piecewise regression models, in how influential survey design factors (sample weights, variance units, and design-based degrees of freedom) are incorporated, in age-adjustment methods, in unit-level logistic regression using survey analysis software versus linear regressions on aggregated proportion estimates transformed to the log-odds scale as implemented in the Joinpoint software, and in the defaults, options, or settings of the two software packages.

This report is focused on survey data and will not address any related or similar issues encountered with nonsurvey data, such as vital statistics data. Moreover, although some National Center for Health Statistics (NCHS) products, such as Health, United States, present tables compiled using aggregated data when record-level data are not readily available for analysis (for example, due to resource constraints or data use agreement requirements), this report focuses on cases where record-level analysis can be conducted. Per the “National Center for Health Statistics Guidelines for Analysis of Trends,” analysts should try to conduct record-level analyses whenever possible (1).

Finally, this report focuses on the process that analysts use when conducting trend analyses and making decisions rather than on how results should be presented. It is not intended to be exhaustive or to provide specific solutions, as analysts may encounter many different scenarios. Instead, it provides recommendations, cautions, and information that analysts can use to make decisions during analysis.