# Appendix IV: Example Transforming the Variance–covariance Matrix of Proportions to the Log-odds Scale Using SUDAAN and SAS

This example uses record-level data from the 2007–2018 National Health Interview Survey public-use person files to estimate trends in the percentage of U.S. adults ages 18–64 who were uninsured at the time of the interview. An adult was defined as uninsured if they did not have any private health insurance, Medicare, Medicaid, state Children’s Health Insurance Program (CHIP), state-sponsored or other government-sponsored health plan, or military plan. An adult was also defined as uninsured if they had only Indian Health Service coverage or had only a private plan that paid for one type of service, such as accidents or dental care.

## Data Preparation

libname a ‘Pathname for accessing NHIS data’ access=readonly;

data nhis; set a.nhis2007-a.nhis2018; run;

data nhis2; set nhis;

*Defining PSU and STRAT because combining survey years with different sample designs;

if 2007 le srvy_yr le 2015 then do;

psu=psu_p;

strat=strat_p+1000;

end;

else if 2016 le srvy_yr le 2018 then do;

psu=ppsu;

strat=pstrat+2000;

end;

*Defining NOINS using the NOTCOV variable to represent the uninsured;

if notcov in (7,8,9) then noins=.;

else if notcov=2 then noins=0;

else if notcov=1 then noins=1;

*Defining AGEGRP to identify the subpopulation (adults 18–64 years);

if 18 le age_p le 64 then agegrp=1;

else agegrp=2;

run;

data nhis3; set nhis2 (keep=psu strat wtfa agegrp age_p srvy_yr notcov noins); run;

## Step 1: Obtain Estimates Across Time Using SUDAAN PROC VARGEN

As suggested by the “National Center for Health Statistics Guidelines for Analysis of Trends,” first compute annual survey estimates and plot the data (1). SUDAAN PROC VARGEN may be used to simultaneously obtain percentage estimates (perc), estimates for the proportion of “failures” (1 − p), and estimates of transformed log-odds (logit p) with standard errors. Not all estimates are used to obtain the variance–covariance matrix, but together provide a thorough overview of the overall trend. The data set must be sorted by the survey design variables (PSU and STRAT) before obtaining the estimates.

proc sort data=nhis3; by strat psu; run;

proc vargen data=nhis3 design=wr;

nest strat psu / missunit;

subpopn agegrp=1;

weight wtfa;

class srvy_yr;

xper perc : noins / value = 1 name = “Percent of adults who were uninsured”;

parameter p : perc/100 / name=”Proportion of adults who were uninsured”;

parameter np: 1-p / name=”Proportion of adults who were insured”;

parameter g : log(p/(1-p)) / name=”Logit of p: g(x)”;

output nsum estim seestim varestim / filename=noins nsumFMT=F11.00 estimFMT=F11.10 seestimFMT=F11.10 varestimFMT=F11.10 replace;

run;

proc contents data=noins; run;

proc print data=noins; var srvy_yr variable _c1 nsum estim seestim varestim; where _c1=1; run;

The annual survey estimates and transformed survey estimates produced by PROC VARGEN are displayed in Table XV. Untransformed percentage estimates are plotted in Figure XIV and transformed estimates (log-odds scale) are plotted in Figure XV.

Figure XIV Percentage of U.S. adults ages 18–64 who were uninsured at the time of interview

NOTES: The analytic sample is adults ages 18–64. An adult was defined as uninsured if they did not have any private health insurance, Medicare, Medicaid, Children’s Health Insurance Program (CHIP), state-sponsored or other government-sponsored health plan, or military plan. A person was also defined as uninsured if they had only Indian Health Service coverage or had only a private plan that paid for one type of service, such as accidents or dental care.

SOURCE: National Center for Health Statistics, National Health Interview Survey, Family Core component, 2007–2018.

Figure XIV is a scatterplot of the percentage of U.S. adults ages 18–64 who were uninsured at the time of interview.

Figure XV Natural logarithm of the odds that a U.S. adult ages 18–64 was uninsured at the time of interview

NOTES: The analytic sample is adults ages 18–64. An adult was defined as uninsured if they did not have any private health insurance, Medicare, Medicaid, Children’s Health Insurance Program (CHIP), state-sponsored or other government-sponsored health plan, or military plan. A person was also defined as uninsured if they had only Indian Health Service coverage or had only a private plan that paid for one type of service, such as accidents or dental care.

SOURCE: National Center for Health Statistics, National Health Interview Survey, Family Core component, 2007–2018.

Figure XV is a scatterplot of the natural logarithm of the odds that a U.S. adult ages 18–64 was uninsured at the time of interview.

Table XV

Original and transformed percentages with corresponding standard errors for U.S. adults ages 18–64 who were uninsured at the time of interview, by year

Year | n | Prevalence (weighted percent) | Standard error | Transformed prevalence estimate^1^ | Transformed standard error^2^
2007 | 45,799 | 19.64 | 0.31 | -1.41 | 0.02
2008 | 45,082 | 19.91 | 0.32 | -1.39 | 0.02
2009 | 53,648 | 21.19 | 0.32 | -1.31 | 0.02
2010 | 54,630 | 22.26 | 0.34 | -1.25 | 0.02
2011 | 61,585 | 21.18 | 0.28 | -1.31 | 0.02
2012 | 65,516 | 20.89 | 0.31 | -1.33 | 0.02
2013 | 62,842 | 20.47 | 0.28 | -1.36 | 0.02
2014 | 67,084 | 16.30 | 0.25 | -1.64 | 0.02
2015 | 61,666 | 12.96 | 0.21 | -1.90 | 0.02
2016 | 56,878 | 12.25 | 0.33 | -1.97 | 0.03
2017 | 45,848 | 12.82 | 0.34 | -1.92 | 0.03
2018 | 42,418 | 13.20 | 0.33 | -1.88 | 0.03

1 Percentages were rescaled to proportions (p = percent/100) and then transformed to the log odds scale by applying the formula ln(p/(1 − p)).

2 Standard errors of the prevalence estimates were rescaled to be standard errors of proportions and then transformed to the log odds scale by applying the formula se(p)/(p • (1 − p)).

NOTES: An adult was defined as uninsured if they did not have any private health insurance, Medicare, Medicaid, state Children’s Health Insurance Program (CHIP), state-sponsored or other government-sponsored health plan, or military plan. A person was also defined as uninsured if they had only Indian Health Service coverage or had only a private plan that paid for one type of service, such as accidents or dental care.

SOURCE: National Center for Health Statistics, National Health Interview Survey, Family Core component, 2007–2018.

## Step 2: Obtain the Variance–covariance Matrix for Estimated Proportions Across Time Using PROC SURVEYMEANS in SAS/STAT Survey Procedures

SAS PROC SURVEYMEANS produces estimates and standard errors for proportions (p) but does not include the complement (1 − p).

proc surveymeans data=nhis3;

cluster psu;

strata strat;

weight wtfa;

var noins;

domain agegrp*srvy_yr / dfadj cov;

ods output

Domain=noinsp

DomainMeanCov=noinscov;

run;

proc print data=noinscov; where agegrp=1; run;

The variance–covariance matrix for estimated proportions across time, displayed through PROC PRINT, is provided in Table XVI.

Table XVI

Output from SAS/STAT representing the variance–covariance matrix for the proportion of adults ages 18–64 who were uninsured at the time of interview, by year

SRVY_YR^1^ | Cov1 | Cov2 | Cov3 | Cov4 | Cov5 | Cov6 | Cov7 | Cov8 | Cov9 | Cov10 | Cov11 | Cov12
2007 | 0.0000096 | 0.0000025 | 0.0000029 | 0.0000025 | 0.0000017 | 0.0000026 | 0.0000018 | 0.0000014 | 0.0000018 | 0.0000000 | 0.0000000 | 0.0000000
2008 | 0.0000025 | 0.0000100 | 0.0000033 | 0.0000020 | 0.0000018 | 0.0000012 | 0.0000015 | 0.0000011 | 0.0000013 | 0.0000000 | 0.0000000 | 0.0000000
2009 | 0.0000029 | 0.0000033 | 0.0000100 | 0.0000030 | 0.0000024 | 0.0000027 | 0.0000019 | 0.0000012 | 0.0000013 | 0.0000000 | 0.0000000 | 0.0000000
2010 | 0.0000025 | 0.0000020 | 0.0000030 | 0.0000120 | 0.0000031 | 0.0000023 | 0.0000025 | 0.0000018 | 0.0000016 | 0.0000000 | 0.0000000 | 0.0000000
2011 | 0.0000017 | 0.0000018 | 0.0000024 | 0.0000031 | 0.0000081 | 0.0000038 | 0.0000031 | 0.0000017 | 0.0000017 | 0.0000000 | 0.0000000 | 0.0000000
2012 | 0.0000026 | 0.0000012 | 0.0000027 | 0.0000023 | 0.0000038 | 0.0000095 | 0.0000034 | 0.0000028 | 0.0000016 | 0.0000000 | 0.0000000 | 0.0000000
2013 | 0.0000018 | 0.0000015 | 0.0000019 | 0.0000025 | 0.0000031 | 0.0000034 | 0.0000078 | 0.0000025 | 0.0000017 | 0.0000000 | 0.0000000 | 0.0000000
2014 | 0.0000014 | 0.0000011 | 0.0000012 | 0.0000018 | 0.0000017 | 0.0000028 | 0.0000025 | 0.0000065 | 0.0000014 | 0.0000000 | 0.0000000 | 0.0000000
2015 | 0.0000018 | 0.0000013 | 0.0000013 | 0.0000016 | 0.0000017 | 0.0000016 | 0.0000017 | 0.0000014 | 0.0000046 | 0.0000000 | 0.0000000 | 0.0000000
2016 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000110 | 0.0000068 | 0.0000054
2017 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000068 | 0.0000120 | 0.0000059
2018 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000054 | 0.0000059 | 0.0000110

1 Represents survey year.

NOTES: SAS/STAT output comes from PROC SURVEYMEANS and PROC PRINT. An adult was defined as uninsured if they did not have any private health insurance, Medicare, Medicaid, Children’s Health Insurance Program (CHIP), state-sponsored or other government-sponsored health plan, or military plan. A person was also defined as uninsured if they had only Indian Health Service coverage or had only a private plan that paid for one type of service, such as accidents or dental care. Cov1–Cov12 represent untransformed covariance estimates associated with estimated proportions across time.

SOURCE: National Center for Health Statistics, National Health Interview Survey, Family Core component, 2007–2018.

## Step 3: Combine Estimated Proportions With Variance–covariance Data to Create a Final Data Set of the Untransformed Variance–covariance Matrix

Combine estimated proportions (p) from step 2 (data set: estim) with the variance–covariance data set from step 2 (data set: cov) to create a data set (covp) of the form shown below (Table XVII). A new variable (np) is defined to represent the complement of p. The variable ‘srvy_yr’ serves as the id variable for merging and represents the year of the survey labeled 2007 through 2018.

Table XVII

Output from SAS/STAT representing the combined data set

SRVY_YR^1^ | p | np | Cov1 | Cov2 | Cov3 | Cov4 | Cov5 | Cov6 | Cov7 | Cov8 | Cov9 | Cov10 | Cov11 | Cov12
2007 | 0.196370 | 0.80363 | 0.0000096 | 0.0000025 | 0.0000029 | 0.0000025 | 0.0000017 | 0.0000026 | 0.0000018 | 0.0000014 | 0.0000018 | 0.0000000 | 0.0000000 | 0.0000000
2008 | 0.199137 | 0.80086 | 0.0000025 | 0.0000100 | 0.0000033 | 0.0000020 | 0.0000018 | 0.0000012 | 0.0000015 | 0.0000011 | 0.0000013 | 0.0000000 | 0.0000000 | 0.0000000
2009 | 0.211925 | 0.78808 | 0.0000029 | 0.0000033 | 0.0000100 | 0.0000030 | 0.0000024 | 0.0000027 | 0.0000019 | 0.0000012 | 0.0000013 | 0.0000000 | 0.0000000 | 0.0000000
2010 | 0.222628 | 0.77737 | 0.0000025 | 0.0000020 | 0.0000030 | 0.0000120 | 0.0000031 | 0.0000023 | 0.0000025 | 0.0000018 | 0.0000016 | 0.0000000 | 0.0000000 | 0.0000000
2011 | 0.211819 | 0.78818 | 0.0000017 | 0.0000018 | 0.0000024 | 0.0000031 | 0.0000081 | 0.0000038 | 0.0000031 | 0.0000017 | 0.0000017 | 0.0000000 | 0.0000000 | 0.0000000
2012 | 0.208892 | 0.79111 | 0.0000026 | 0.0000012 | 0.0000027 | 0.0000023 | 0.0000038 | 0.0000095 | 0.0000034 | 0.0000028 | 0.0000016 | 0.0000000 | 0.0000000 | 0.0000000
2013 | 0.204743 | 0.79526 | 0.0000018 | 0.0000015 | 0.0000019 | 0.0000025 | 0.0000031 | 0.0000034 | 0.0000078 | 0.0000025 | 0.0000017 | 0.0000000 | 0.0000000 | 0.0000000
2014 | 0.163022 | 0.83698 | 0.0000014 | 0.0000011 | 0.0000012 | 0.0000018 | 0.0000017 | 0.0000028 | 0.0000025 | 0.0000065 | 0.0000014 | 0.0000000 | 0.0000000 | 0.0000000
2015 | 0.129551 | 0.87045 | 0.0000018 | 0.0000013 | 0.0000013 | 0.0000016 | 0.0000017 | 0.0000016 | 0.0000017 | 0.0000014 | 0.0000046 | 0.0000000 | 0.0000000 | 0.0000000
2016 | 0.122485 | 0.87751 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000110 | 0.0000068 | 0.0000054
2017 | 0.128160 | 0.87184 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000068 | 0.0000120 | 0.0000059
2018 | 0.132002 | 0.86800 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000054 | 0.0000059 | 0.0000110

1 Represents survey year.

NOTES: SAS/STAT output comes from SAS PROC PRINT. The combined dataset (covp) includes the estimated proprortions of adults ages 18–64 who were uninsured at the time of interview (p), the complements of the proportions (np), and the variance–covariance data set (cov) for estimates by survey year (SRVY_YR). Cov1–Cov12 represent untransformed covariance estimates associated with estimated proportions by year.

SOURCE: National Center for Health Statistics, National Health Interview Survey, Family Core component, 2007–2018.

data estim; set noinsp; if agegrp=1;

np=1-mean;

rename mean=p;

drop DomainLabel LowerCLMean StdErr UpperCLMean VarName agegrp;

run;

proc print data=estim; run;

data cov; set noinscov (keep=srvy_yr agegrp cov1-cov12); if agegrp=1;

drop agegrp;

run;

proc print data=cov; run;

proc sort data=estim; by srvy_yr; run;

proc sort data=cov; by srvy_yr; run;

data covp; merge estim cov; by srvy_yr; run;

proc print data=covp; run;

## Step 4: Use SAS PROC IML and the Data Set Produced in Step 3 to Obtain the Transformed Variance–covariance Matrix

proc iml;

varNames = {“p” “np” “cov1” “cov2” “cov3” “cov4” “cov5” “cov6” “cov7” “cov8” “cov9” “cov10” “cov11” “cov12”};

use covp;

read all var varNames into j2;

close covp;

print j2[c=varNames];

covl = j(12,12,1);

do i=1 to 12;

do j=1 to 12;

covl[i,j]=j2[i,j+2]/(j2[i,1]*j2[i,2]*j2[j,1]*j2[j,2]);

end;

end;

print covl;

create covl from covl;

append from covl;

show contents;

close covl;

print covl;

data covlogit; set covl; run;

proc print data=covlogit; run;

The variance–covariance matrix for proportions, transformed to the log-odds scale and displayed via PROC PRINT, is presented in Table XVIII.

Table XVIII

Input data for Joinpoint regression software obtained using SAS PROC IML and representing the variance–covariance matrix for the proportion of adults ages 18–64 who were uninsured at the time of interview

COL1 | COL2 | COL3 | COL4 | COL5 | COL6 | COL7 | COL8 | COL9 | COL10 | COL11 | COL12
0.0003857 | 0.0001008 | 0.0001104 | 0.0000911 | 0.0000650 | 0.0001012 | 0.0000692 | 0.0000666 | 0.0000983 | 0.0000000 | 0.0000000 | 0.0000000
0.0001008 | 0.0004064 | 0.0001249 | 0.0000718 | 0.0000675 | 0.0000439 | 0.0000564 | 0.0000527 | 0.0000726 | 0.0000000 | 0.0000000 | 0.0000000
0.0001104 | 0.0001249 | 0.0003711 | 0.0001053 | 0.0000870 | 0.0000979 | 0.0000710 | 0.0000514 | 0.0000706 | 0.0000000 | 0.0000000 | 0.0000000
0.0000911 | 0.0000718 | 0.0001053 | 0.0003936 | 0.0001063 | 0.0000811 | 0.0000893 | 0.0000751 | 0.0000805 | 0.0000000 | 0.0000000 | 0.0000000
0.0000650 | 0.0000675 | 0.0000870 | 0.0001063 | 0.0002891 | 0.0001382 | 0.0001148 | 0.0000744 | 0.0000920 | 0.0000000 | 0.0000000 | 0.0000000
0.0001012 | 0.0000439 | 0.0000979 | 0.0000811 | 0.0001382 | 0.0003487 | 0.0001246 | 0.0001252 | 0.0000880 | 0.0000000 | 0.0000000 | 0.0000000
0.0000692 | 0.0000564 | 0.0000710 | 0.0000893 | 0.0001148 | 0.0001246 | 0.0002924 | 0.0001121 | 0.0000923 | 0.0000000 | 0.0000000 | 0.0000000
0.0000666 | 0.0000527 | 0.0000514 | 0.0000751 | 0.0000744 | 0.0001252 | 0.0001121 | 0.0003465 | 0.0000907 | 0.0000000 | 0.0000000 | 0.0000000
0.0000983 | 0.0000726 | 0.0000706 | 0.0000805 | 0.0000920 | 0.0000880 | 0.0000923 | 0.0000907 | 0.0003608 | 0.0000000 | 0.0000000 | 0.0000000
0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0009193 | 0.0005648 | 0.0004371
0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0005648 | 0.0009345 | 0.0004620
0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0000000 | 0.0004371 | 0.0004620 | 0.0008543

NOTES: Each row in the table represents a survey year. The columns COL1–COL12 represent the covariance estimates associated with the log odds-transformed proportions for each of the 12 years from 2007 to 2018. The terms COL1–COL12 represent generic names produced from the SAS PROC IML code. Column names are not used in Joinpoint software when uploading the variance–covariance matrix.

SOURCE: National Center for Health Statistics, National Health Interview Survey, Family Core component, 2007–2018.

This variance-covariance matrix for proportions, transformed to the log-odds scale (Table XVIII), can then be input into the National Cancer Institute’s Joinpoint Regression Software under the correlated errors option to continue evaluating the trend by assessing the number and location of joinpoints. Note that column headers must be removed before reading the variance-covariance matrix into the Joinpoint software.

In this example, both the untransformed and transformed variance-covariance matrices demonstrate independence between survey years with different sample designs (COL1–COL9 versus COL10–COL12). In these cases, no overlap in PSU and strata variables across time exists, and so the covariance terms associated with two estimates from different designs equal zero. Similar observations would be made for the entire matrix (off-diagonal elements) if using a data set such as the National Health and Nutrition Examination Survey, which assumes independence of PSUs and strata across time.