# Appendix III: Implementing the Transformation of the Variance–covariance Matrix of Proportions to the Log-odds Scale Using SUDAAN and SAS

## Step 1: Obtain Estimates Across Time Using SUDAAN PROC VARGEN

Estimates include percentages (perc), proportion of “successes” (p), proportion of “failures” (1 − p), and transformed prevalences (logit p). While not all estimates obtained by SUDAAN PROC VARGEN will be used to obtain the variance–covariance matrix, together the estimates provide a thorough overview of the overall trend. The data set must be sorted by the survey design variables (strata and psu) before obtaining the estimates.

proc sort data=<DATA SET>; by <STRATA VARIABLE> <PSU VARIABLE>; run;

proc vargen data=<DATA SET> design=<DESIGN OPTION>;

nest <STRATA VARIABLE> <PSU VARIABLE> / missunit;

subpopn <SUBGROUP OF INTEREST>;

weight <WEIGHT VARIABLE>;

class <TIMEPOINT VARIABLE>;

xper perc : <BINARY VARIABLE OF INTEREST> / value = <0 or 1: outcome of interest> name = “Percent of …”;

parameter p : perc/100 / name=”Proportion of …”;

parameter np: 1-p / name=”Proportion of …”;

parameter g : log(p/(1-p)) / name=”Logit of p: g(x)”;

output nsum estim seestim varestim / filename=<NEW DATA SET NAME> nsumFMT=F##.## estimFMT=F##.## seestimFMT=F##.## varestimFMT=F##.## replace;

run;

## Step 2: Obtain the Variance–covariance Matrix for Estimated Proportions Across Time Using SAS PROC SURVEYMEANS in SAS/STAT Survey Procedures

SAS PROC SURVEYMEANS produces estimates and standard errors for proportions (p) but does not include (1 − p).

proc surveymeans data=<DATA SET>;

cluster <PSU VARIABLE>;

strata <STRATA VARIABLE>;

weight <WEIGHT VARIABLE>;

var <BINARY VARIABLE OF INTEREST>;

domain <SUBGROUP OF INTEREST*TIMEPOINT VARIABLE> / dfadj cov;

ods output

Domain=<DATA SET OF ESTIMATES>

DomainMeanCov=<DATA SET OF VARIANCE-COVARIANCE ESTIMATES>;

run;

## Step 3: Combine Estimated Proportions With Variance–covariance Data to Create a Final Data Set of the Untransformed Variance–covariance Matrix

Combine estimated proportions (p) from step 2 (DATA SET OF ESTIMATES: time point, variable p) with variance–covariance data set from step 2 (DATA SET OF VARIANCE–COVARIANCE ESTIMATES: cov1, cov2, … covn) to create a data set of the form shown below (Table XIII). A new variable (np) is defined to represent the complement of p at each time point. The time point variable serves as the id variable for merging and may be numbered as preferred by the analyst (examples: 1 through n, year, survey cycle). The time point variable is not used in step 4 (SAS PROC IML).

Table XIII

Example output for Step 3

TIMEPT | P | NP | COV1 | COV2 | COV3 | … | COVN
1 | 0.## | 1-p | 0.## | 0.## | 0.## | … | 0.##
2 | 0.## | 1-p | 0.## | 0.## | 0.## | … | 0.##
3 | 0.## | 1-p | 0.## | 0.## | 0.## | … | 0.##
4 | 0.## | 1-p | 0.## | 0.## | 0.## | … | 0.##
5 | 0.## | 1-p | 0.## | 0.## | 0.## | … | 0.##
6 | 0.## | 1-p | 0.## | 0.## | 0.## | … | 0.##
7 | 0.## | 1-p | 0.## | 0.## | 0.## | … | 0.##
8 | 0.## | 1-p | 0.## | 0.## | 0.## | … | 0.##
9 | 0.## | 1-p | 0.## | 0.## | 0.## | … | 0.##
| 0.##
n | 0.## | 1-p | 0.## | 0.## | 0.## | … | 0.##

SOURCE: National Center for Health Statistics.

data <DATA SET OF ESTIMATES VERSION 2>; set <DATA SET OF ESTIMATES>; if <IDENTIFY SUBGROUP OF INTEREST>;

np=1-mean;

rename mean=p;

drop DomainLabel LowerCLMean N StdErr UpperCLMean VarName <VARIABLES RELATED TO SUBGROUP OF INTEREST>;

run;

proc print data=<DATA SET OF ESTIMATES VERSION 2>; run;

data <DATA SET OF VARIANCE-COVARIANCE ESTIMATES VERSION 2>; set <DATA SET OF VARIANCE-COVARIANCE ESTIMATES> (keep=<TIMEPOINT VARIABLE> <VARIABLES RELATED TO SUBGROUP OF INTEREST> COV1-<COVN>); if <IDENTIFY SUBGROUP OF INTEREST>;

drop <VARIABLES RELATED TO SUBGROUP OF INTEREST>;

run;

proc print data=<DATA SET OF VARIANCE-COVARIANCE ESTIMATES VERSION 2>; run;

proc sort data=<DATA SET OF ESTIMATES VERSION 2>; by <TIMEPOINT VARIABLE>; run;

proc sort data=<DATA SET OF VARIANCE-COVARIANCE ESTIMATES VERSION 2>; by <TIMEPOINT VARIABLE>; run;

data <FINAL DATA SET OF UNTRANSFORMED VARIANCE-COVARIANCE ESTIMATES>; merge <DATA SET OF ESTIMATES VERSION 2> <DATA SET OF VARIANCE-COVARIANCE ESTIMATES VERSION 2>; by <TIMEPOINT VARIABLE>; run;

proc print data=<FINAL DATA SET OF UNTRANSFORMED VARIANCE-COVARIANCE ESTIMATES>; run;

Example output from the final PROC PRINT is provided in Table XIII.

## Step 4: Use SAS PROC IML and the Data Set Created in Step 3 to Obtain the Transformed Variance–covariance Matrix

The transformed variance–covariance matrix is associated with the transformed estimates:

ln ((p^_1_)/(1 − p^_1_)) , ln ((p^_2_)/(1 − p^_2_)) , ... , ln ((p^_i + ( n − 1 )_)/(1 − p^_i + ( n − 1 )_)) [ l o g - o d d s s c a l e ]

proc iml;

varNames = {“p” “np” “cov1” “cov2” “cov3” “cov4” “cov5” “cov6” “cov7” “cov8” “cov9” ... “cov<N>”};

use <FINAL DATA SET OF UNTRANSFORMED VARIANCE-COVARIANCE ESTIMATES>;

read all var varNames into j2;

close <FINAL DATA SET OF UNTRANSFORMED VARIANCE-COVARIANCE ESTIMATES>;

print j2[c=varNames];

<DATA SET OF TRANSFORMED VARIANCE-COVARIANCE ESTIMATES> = j(<N>,<N>,1);

do i=1 to <N>;

do j=1 to <N>;

<DATA SET OF TRANSFORMED VARIANCE-COVARIANCE ESTIMATES>[i,j]=j2[i,j+2]/(j2[i,1]*j2[i,2]*j2[j,1]*j2[j,2]);

end;

end;

print <DATA SET OF TRANSFORMED VARIANCE-COVARIANCE ESTIMATES>;

create <DATA SET OF TRANSFORMED VARIANCE-COVARIANCE ESTIMATES> from <DATA SET OF TRANSFORMED VARIANCE-COVARIANCE ESTIMATES>;

append from <DATA SET OF TRANSFORMED VARIANCE-COVARIANCE ESTIMATES>;

show contents;

close <DATA SET OF TRANSFORMED VARIANCE-COVARIANCE ESTIMATES>;

print <DATA SET OF TRANSFORMED VARIANCE-COVARIANCE ESTIMATES>;

/*To save as a SAS data set*/

data <DATA SET OF TRANSFORMED VARIANCE-COVARIANCE ESTIMATES>; set <DATA SET OF TRANSFORMED VARIANCE-COVARIANCE ESTIMATES>; run;

proc print data=<DATA SET OF TRANSFORMED VARIANCE-COVARIANCE ESTIMATES>; run;

Example output from the final PROC PRINT is provided in Table XIV.

Table XIV

Example output for Step 4

COL1 | COL2 | COL3 | … | COLN
#.# | #.# | #.# | … | #.#
#.# | #.# | #.# | … | #.#
#.# | #.# | #.# | … | #.#
⋮ | ⋮ | ⋮ | ⋮ | ⋮
#.# | #.# | #.# | … | #.#

SOURCE: National Center for Health Statistics.

This variance–covariance matrix, transformed to the log-odds scale, can then be input into the National Cancer Institute’s Joinpoint Regression Software under the correlated errors option to continue evaluating the trend by assessing the number and location of joinpoints. Note that column headers must be removed before reading the variance–covariance matrix into the Joinpoint software and that it is often advantageous to save the variance–covariance matrix as a CSV (comma-separated value) text file first.