# Appendix II: Transforming the Variance–covariance Matrix of Proportions to the Log-odds Scale

As described in Issues 8 and 12 and demonstrated in Example B and Appendix VI of the “National Center for Health Statistics Guidelines for Analysis of Trends,” logistic regression is often used to model a time trend for survey data when the outcome variable is binary (1). If the trend is nonlinear and the National Cancer Institute Joinpoint Regression Software is used to identify the number and location of joinpoints, it is preferable to transform the proportions and standard errors to the log-odds scale before inputting to the Joinpoint software.

This transformation can be achieved as identified in Appendix VI of the “National Center for Health Statistics Guidelines for Analysis of Trends” and as described on page 32 of Cox’s The Analysis of Binary Data (23):

1. Transform the original proportion, p̂, as follows:

ln ( (p^)/(1 − p^) ) Natural logarithm of the fraction p hat over one minus p hat

2. Transform the original estimated standard error, se(p̂), as follows:

(s e^ ( p^ ))/(p^ ( 1 − p^ )) standard error of p hat

Here, the covariance of P_i _and P_i + 1_ is transformed to the log-odds (logit) scale. This can be used by the analyst to transform the original variance–covariance matrix for a series of n estimated proportions p̂_i_, p̂_i+1_, …, p̂_i+(n−1)_ collected at time points i through {i + (n − 1)} into a variance–covariance matrix for

ln ((p^_1_)/(1 − p^_1_)) , ln ((p^_2_)/(1 − p^_2_)) , ... , ln ((p^_i + ( n − 1 )_)/(1 − p^_i + ( n − 1 )_)) A series from p hat sub i to p hat sub i plus n minus one

For clarity, let P_i_ = X and P_i + 1_ = Y. Let X be collected at time point i, and Y at time point i + 1. Then X~(μ_X_, Var(X)) and Y~(μ_Y_, Var(Y)), where μ_X_ and μ_Y_ are proportions. Define

g ( x ) = l o g i t ( x ) = l n ( (x)/(1 − x) ) Function g of x equals logit of x, which is equal to the natural logarithm of x divided by one minus x

,

g ( y ) = l o g i t ( y ) = l n ( (y)/(1 − y) ) Function g of y equals logit of y, which is equal to the natural logarithm of y divided by one minus y

U = g(X), and V = g(Y). The goal is to obtain the covariance of U and V.

By definition, Cov(U,V ) = E(UV ) − E(U)E(V ) = E[g(X )g(Y )] − E [g(X )]E [g(Y )]

Using the first-order Taylor series expansions of g(X) and g(Y) around the expected values E[X] and E[Y], respectively,

C o v ( U , V ) ≈ E [ ( g ( E ( X ) ) + g^′^ ( E ( X ) ) · ( X − E ( X ) ) ) · ( g ( E ( Y ) ) + g^′^ ( E ( Y ) ) · ( Y − E ( Y ) ) ) ] − E [ g ( X ) ] · E [ g ( Y ) ] Covariance of U and V is approximately equal to the expected value of the product of g of the expected value of X plus the derivative of g at the expected value of X multiplied by the difference between X and the expected value of X, and g of the expected value of Y plus the derivative of g at the expected value of Y multiplied by the difference between Y and the expected value of Y, minus the expected value of g of X multiplied by the expected value of g of Y

C o v ( U , V ) ≈ E [ g ( E ( X ) ) · g ( E ( Y ) ) + g ( E ( X ) ) · g^′^ ( E ( Y ) ) · ( Y − E ( Y ) ) + g ( E ( Y ) ) · g^′^ ( E ( X ) ) · ( X − E ( X ) ) + g^′^ ( E ( X ) ) · g^′^ ( E ( Y ) ) · ( X − E ( X ) ) · ( Y − E ( Y ) ) ] − E [ g ( X ) ] · E [ g ( Y ) ] The covariance of U and V is approximately equal to the expected value of the sum of g of the expected value of X multiplied by g of the expected value of Y, plus g of the expected value of X multiplied by the derivative of g at the expected value of Y multiplied by the difference between Y and the expected value of Y, plus g of the expected value of Y multiplied by the derivative of g at the expected value of X multiplied by the difference between X and the expected value of X, plus the derivative of g at the expected value of X multiplied by the derivative of g at the expected value of Y multiplied by the difference between X and the expected value of X multiplied by the difference between Y and the expected value of Y, minus the expected value of g of X multiplied by the expected value of g of Y

Recall that:

E [ g ( E ( X ) ) · g^′^ ( E ( Y ) ) · ( Y − E ( Y ) ) ] = c_1_ · c_2_ · E [ Y − E ( Y ) ] = 0

where c_1_ and c_2_ are constants,

E [ g ( E ( Y ) ) · g^′^ ( E ( X ) ) · ( X − E ( X ) ) ] = c_3_ · c_4_ · E [ X − E ( X ) ] = 0

where c_3_ and c_4_ are constants, and

E [ ( X − E ( X ) ) · ( Y − E ( Y ) ) ] = C o v ( X , Y )

Thus,

C o v ( U , V ) ≈ g ( E ( X ) ) · g ( E ( Y ) ) + g^′^ ( E ( X ) ) · g^′^ ( E ( Y ) ) · C o v ( X , Y ) − E ( g ( X ) ) · E ( g ( Y ) )

From the first-order Taylor series expansions of g(X) and g(Y), shown previously, their expected values are

E[g(X)] ≈ g[E(X)] and E[g(Y)] ≈ g[E(Y)]. Therefore,

C o v ( U , V ) ≈ g^′^ ( E ( X ) ) · g^′^ ( E ( Y ) ) · C o v ( X , Y )

Finally, because

g^′^ ( x ) = (1)/(x · ( 1 − x ))

_and_

g^′^ ( y ) = (1)/(y · ( 1 − y ))

it follows that

C o v ( U , V ) ≈ (C o v ( X , Y ))/(E ( X ) · ( 1 − E ( X ) ) · E ( Y ) · ( 1 − E ( Y ) ))

Hence, an estimate for the covariance of the logit(P_i_) and logit(P_i+1_) is:

C o v [ log i t ( P_i_ ) , log i t ( P_i + 1_ ) ] ≈ (C o v ( p^_i_ , p^_i + 1_ ))/(( p^_i_ ) · ( 1 − p^_i_ ) · ( p^_i + 1_ ) · ( 1 − p^_i + 1_ ))