# Appendix I. Illustrative Examples A through D

## Example A. Elevated Blood Lead Levels in Children Ages 1–11 Years: NHANES, 1999–2016

### Overview

This example demonstrates a case in which the test for a linear trend in SUDAAN is statistically significant, higher-order terms are not statistically significant, and the National Cancer Institute’s Joinpoint Regression Software also suggests a linear trend with no joinpoints. In this case, the two software programs agree in terms of the number and placement of joinpoints. Results are consistent. In most instances, this agreement between the two types of software is expected.

### Step 1. Compute estimates for each survey cycle and plot the estimates

Weighted percentage estimates and standard errors by survey cycle in the National Health and Nutrition Examination Survey (NHANES), 1999–2016, are presented in Table I and Figure I. Estimates transformed to the log-odds scale are presented in Table I and Figure II.

Figure I Prevalence of elevated blood lead levels in children ages 1–11 years who were examined at the mobile examination center

NOTES: Prevalence estimates and their standard errors were obtained using record-level data and SUDAAN’s PROC DESCRIPT with mobile examination center weights. Elevated blood lead levels are 5 µg/dL or above.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–2016.

Figure I is a scatterplot of the prevalence of elevated blood lead levels in children ages 1–11 years who were examined at the mobile examination center.

Figure II Transformed prevalence estimates of elevated blood lead levels in children ages 1–11 years who were examined at the mobile examination center

NOTES: Percentage estimates and their standard errors were obtained using record-level data and SUDAAN’s PROC DESCRIPT with mobile examination center weights. Weighted percentages were transformed to the log-odds scale to obtain transformed prevalence estimates. Elevated blood lead levels are 5 µg/dL or greater.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–2016.

Figure II is a scatterplot of the transformed prevalence estimates of elevated blood lead levels in children ages 1–11 years who were examined at the mobile examination center.

Table I

Prevalence estimates, transformed estimates, and standard errors by survey cycle of elevated blood lead levels in children ages 1–11 years who were examined at the mobile examination center

Survey cycle | n | Prevalence(weighted percentage) | Standard error | Transformed prevalence^1^ | Transformed standard error^2^
1999–2000 | 1,611 | 6.17 | 1.20 | -2.72 | 0.21
2001–2002 | 1,931 | 4.43 | 0.88 | -3.07 | 0.21
2003–2004 | 1,754 | 3.07 | 0.89 | -3.45 | 0.30
2005–2006 | 1,893 | 1.98 | 0.52 | -3.90 | 0.27
2007–2008 | 1,813 | 1.67 | 0.52 | -4.07 | 0.32
2009–2010 | 1,836 | 1.01 | 0.20 | -4.58 | 0.20
2011–2012 | 1,750 | 1.00 | 0.37 | -4.60 | 0.37
2013–2014 | 1,869 | 0.30 | 0.15 | -5.82 | 0.50
2015–2016 | 1,802 | 0.67 | 0.30 | -5.00 | 0.45

1 Percentages were rescaled to proportions (p = percent/100) and then transformed to the log odds scale by applying the formula ln(p/(1 − p)).

2 Standard errors of prevalence estimates were rescaled to be standard errors of proportions and then transformed to the log odds scale by applying the formula se(p) / (p • (1 − p)).

NOTES: Prevalence estimates and their standard errors were obtained using record-level data and SUDAAN’s PROC DESCRIPT with mobile examination center weights. Elevated blood lead levels are 5 µg/dL or above.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–2016.

### Step 2. Initial assessment of nonlinearity: Polynomial regression or orthogonal polynomial contrasts

Estimates with standard errors are presented in Table II for the simple logistic regression model and quadratic logistic regression model.

Table II

Logistic regression and quadratic regression estimates with standard errors of elevated blood lead levels in children ages 1–11 years who were examined at the mobile examination center

Model | β_o_ (standard error) | β_1_ (standard error) | β_2_ (standard error)
Model | Intercept | Survey cycle | Survey cycle squared
Simple logistic regression | -2.40 (0.19) | -0.34 (0.04) | …
p values | < 0.0001 | < 0.0001 | …
Quadratic logistic regression | -2.29 (0.31) | -0.43 (0.17) | 0.0097 (0.02)
p values | < 0.0001 | 0.0200 | 0.6200

… Category not applicable.

NOTES: Survey cycles 1999–2000 through 2015–2016 were coded as 1 through 9 for logistic regression analyses. Prevalence estimates and their standard errors were obtained using record-level data and SUDAAN’s PROC RLOGIST. Elevated blood lead levels are 5 µg/dL or above.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–2016.

### Step 3. Estimate the number and location of joinpoints for nonlinear trends using Joinpoint software

For this example, the following options were selected in the Joinpoint software:

1. Log transformation: No
2. Heteroscedastic/correlated errors option: Variance–covariance matrix (provided)
3. Method: Grid search
  a. Minimum number of observations from a joinpoint to either end of the data: Two
  b. Minimum number of observations between two joinpoints: Two
  c. Number of points to place between adjacent observed x values in the grid search: Zero
4. Number of joinpoints:
  a. Minimum: Zero
  b. Maximum: One
5. Model selection method: BIC (fewer than 10 time points).

Automated output from the Joinpoint software (graph and model estimates) are presented in Figure III.

Figure III Joinpoint software’s automated output: Transformed estimates of elevated blood lead levels in children ages 1–11 years who were examined at the mobile examination center* Indicates that the slope is significantly different from zero at the α = 0.05 level. Final selected model has zero joinpoints.^1^Survey cycles 1999–2000 through 2015–2016 were coded as 1 through 9 for logistic regression analyses.

NOTES: Transformed prevalence estimates and their standard errors were obtained using record-level data and SUDAAN’s PROC DESCRIPT with mobile examination center weights. Elevated blood lead levels are 5 µg/dL.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–2016.

Figure III is a scatterplot of the Joinpoint software’s automated output of the transformed estimates of elevated blood lead levels in children ages 1–11 years who were examined at the mobile examination center.

Model number | Number of joinpoints | Number of observations | Number of parameters | Degrees of freedom | Sum of squared errors | BIC
1 | 0 | 9 | 2 | 7 | 3.8983983 | -0.3483831
2 | 1 | 9 | 4 | 5 | 3.3617172 | -0.0082284

### Step 4. Obtain final slope estimates and tests of trend using a standard survey package

Because neither SUDAAN nor Joinpoint software identifies a joinpoint, the simple logistic regression model (Table II) is chosen as the final model (Figure IV).

Figure IV Transformed prevalence estimates of elevated blood lead levels with linear logistic regression line in children ages 1–11 years who were examined at the mobile examination center

^1^Survey cycles 1999–2000 through 2015–2016 were coded as 1 through 9 for logistic regression analyses.

NOTES: Observed prevalence estimates were obtained using record-level data and SUDAAN’s PROC DESCRIPT with mobile examination center weights. For regression estimates, prevalence estimates and their standard errors were obtained using record-level data and SUDAAN’s PROC RLOGIST. Elevated blood lead levels are 5 μg/dL or above. Linear logistic regression line shown is presented in Table II in this report.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–2016.

Figure IV is a scatterplot of the transformed prevalence estimates of elevated blood lead levels with linear logistic regression line in children ages 1–11 years who were examined at the mobile examination center.

### Conclusions

Based on SUDAAN, the best model for the data is the simple logistic regression presented in step 2 (Table II, Figure IV). In conclusion, the prevalence of high lead levels in children ages 1–11 decreased steadily between 1999–2000 and 2015–2016.

### Explanation of differences

Results are consistent.

## Example B. Employment Rate Among People Age 16 and Older in the U.S. Labor Force: 1999–2017 Current Population Survey Annual Social and Economic Supplements

### Overview

This example demonstrates a case in which the test for a quadratic trend using SAS PROC SURVEY commands is statistically significant; a test for a cubic trend using SAS PROC SURVEY commands is statistically significant; the Joinpoint software suggests three joinpoints at 2002, 2006, and 2009; and the piecewise regression using SAS PROC SURVEY commands indicates that the changes in slope between all adjacent slope estimates are statistically significant. In this case, the results based on SAS PROC SURVEY commands match the results based on the Joinpoint software (in terms of the number and placement of joinpoints). Results are consistent. In most instances, this agreement between the two types of software is expected.

### Step 1: Compute annual survey estimates and plot the estimates

Weighted proportions and standard errors by survey cycle are presented in Table III and Figure V.

Figure V Employment rate among people age 16 and older in the U.S. labor force

NOTES: People are considered employed if they are employed during the survey week. Labor force includes people who have a job and people who are jobless, looking for a job, and available for work.

SOURCE: U.S. Census Bureau, Current Population Survey Annual Social and Economic Supplement, 1999–2017.

Figure V is a scatterplot of the employment rate among people age 16 and older in the U.S. labor force.

Table III

Weighted proportions and standard errors by year of the employment rate among people age 16 and older in the U.S. labor force

Year | n | Weighted proportion | Standard error
1999 | 68,013 | 0.96 | 0.0009
2000 | 65,441 | 0.95 | 0.0010
2001 | 107,933 | 0.94 | 0.0009
2002 | 106,923 | 0.94 | 0.0009
2003 | 105,217 | 0.94 | 0.0009
2004 | 103,893 | 0.94 | 0.0009
2005 | 103,339 | 0.95 | 0.0008
2006 | 102,984 | 0.95 | 0.0008
2007 | 103,086 | 0.95 | 0.0009
2008 | 103,329 | 0.91 | 0.0011
2009 | 103,660 | 0.90 | 0.0011
2010 | 100,683 | 0.91 | 0.0011
2011 | 98,822 | 0.91 | 0.0011
2012 | 98,735 | 0.92 | 0.0010
2013 | 67,864 | 0.93 | 0.0012
2014 | 95,984 | 0.94 | 0.0009
2015 | 89,494 | 0.95 | 0.0009
2016 | 90,079 | 0.95 | 0.0008
2017 | 87,138 | 0.96 | 0.0008

NOTES: Prevalence estimates and their standard errors were obtained using record-level data and PROC SURVEYMEANS in SAS. People are considered employed if they are employed during the survey week. Labor force includes people who have a job and people who are jobless, looking for a job, and available for work.

SOURCE: U.S. Census Bureau, Current Population Survey Annual Social and Economic Supplement, 1999–2017.

### Step 2: Initial assessment of nonlinearity: Polynomial regression or orthogonal polynomial contrasts

Estimates with standard errors are presented in Table IV for the simple linear regression model, quadratic regression model, and cubic regression model.

Table IV

Linear regression, quadratic regression, and cubic regression estimates with standard errors of the employment rate among people age 16 and older in the U.S. labor force

Model | β_o_ (standard error) | β_1_ (standard error) | β_2_ (standard error) | β_3_ (standard error)
Model | Intercept | Year | Year squared | Year cubed
Simple linear regression | 0.94 (0.0004) | -0.0004 (0.00004) | … | …
p values | < 0.0001 | < 0.0001 | … | …
Quadratic regression | 0.96 (0.0006) | -0.008 (0.0002) | 0.0004 (0.000008) | …
p values | < 0.0001 | < 0.0001 | < 0.0001 | …
Cubic regression | 0.95 (0.0007) | 0.001 (0.0003) | -0.001 (0.00005) | 0.00005 (0.000002)
p values | < 0.0001 | < 0.0001 | < 0.0001 | < 0.0001

… Category not applicable.

NOTES: Prevalence estimates and their standard errors were obtained using record-level data and PROC SURVEYREG in SAS. People are considered employed if they are employed during the survey week. Labor force includes people who have a job and people who are jobless, looking for a job, and available for work.

SOURCE: U.S. Census Bureau, Current Population Survey Annual Social and Economic Supplement, 1999–2017.

### Step 3: Estimate the number and location of joinpoints for nonlinear trends using Joinpoint software

For this example, the following options were selected in the Joinpoint software:

1. Log transformation: No
2. Heteroscedastic/correlated errors option: Variance–covariance matrix (provided)
3. Method: Grid search
  a. Minimum number of observations from a joinpoint to either end of the data: Two
  b. Minimum number of observations between two joinpoints: Two
  c. Number of points to place between adjacent observed x values in the grid search: Zero
4. Number of joinpoints:
  a. Minimum: Zero
  b. Maximum: Three
5. Model selection method: Permutation test (10 or more time points).

Automated output from the Joinpoint software (graph and model estimates) are presented in Figure VI.

Figure VI Joinpoint software’s automated output: Employment rate among people age 16 and older in the U.S. labor force* Indicates that the slope is significantly different from zero at the α = 0.05 level. Final selected model has three joinpoints.

NOTES: People are considered employed if they are empoyed during the survey week. Labor force includes people who have a job and people who are jobless, looking for a job, and available for work.

SOURCE: U.S. Census Bureau, Current Population Survey Annual Social and Economic Supplement, 1999–2017.

Figure VI is a scatterplot of the Joinpoint software’s automated output of the employment rate among people age 16 and older in the U.S. labor force.

Test number | Null hypothesis | Alternate hypothesis | Degrees of freedom | | Number of permutations | p value | Significance level
Test number | Null hypothesis | Alternate hypothesis | Numerator | Denominator | Number of permutations | p value | Significance level
1 | 0 joinpoint(s) | 3 joinpoint(s) | 6 | 11 | 4500 | 0.0002222 | 0.0166667
2 | 1 joinpoint(s) | 3 joinpoint(s) | 4 | 11 | 4500 | 0.0002222 | 0.0250000
3 | 2 joinpoint(s) | 3 joinpoint(s) | 2 | 11 | 4500 | 0.0126667 | 0.0500000

### Step 4: Obtain final slope estimates and tests of trend using a standard survey package

Final estimates with standard errors for the prespecified model recommended by the Joinpoint software and obtained using SAS/STAT survey procedures are presented in Table V. A visual display is provided in Figure VII.

Figure VII Final piecewise regression model for the employment rate among people age 16 and older in the U.S. labor force

NOTES: People are considered employed if they are employed during the survey week. Labor force includes people who have a job and people who are jobless, looking for a job, and available for work. Piecewise regression model shown is presented in Table V in this report.

SOURCE: U.S. Census Bureau, Current Population Survey Annual Social and Economic Supplement, 1999–2017.

Figure VII is a scatterplot of the final piecewise regression model for the employment rate among people age 16 and older in the U.S. labor force.

Table V

Final piecewise regression estimates with standard errors for the employment rate among people age 16 and older in the U.S. labor force

Model components | β | Standard error | p value
Intercept | 0.96 | 0.0008 | < 0.0001
1st line segment (1999–2002) | -0.01 | 0.0004 | < 0.0001
2nd line segment (2002–2006) | 0.01 | 0.0002 | < 0.0001
3rd line segment (2006–2009) | -0.02 | 0.0003 | < 0.0001
4th line segment (2009–2017) | 0.01 | 0.0001 | < 0.0001
Change in slopes (1 versus 2) | 0.01 | 0.0005 | < 0.0001
Change in slopes (2 versus 3) | -0.02 | 0.0005 | < 0.0001
Change in slopes (3 versus 4) | 0.03 | 0.0004 | < 0.0001

NOTES: People are considered employed if they are employed during the survey week. Labor force includes people who have a job and people who are jobless, looking for a job, and available for work.

SOURCE: U.S. Census Bureau, Current Population Survey Annual Social and Economic Supplement, 1999–2017.

### Conclusions

Based on SAS/STAT survey procedures, the best model for the 1999–2017 data is the piecewise regression model presented in step 4 (Table V, Figure VII). This corresponds to the model selected by the Joinpoint software and includes joinpoints at 2002, 2006, and 2009. In conclusion, the employment rate declined steadily between 1999 and 2002, increased steadily between 2002 and 2006, declined sharply between 2006 and 2009, and increased steadily between 2009 and 2017.

### Explanation of differences

Results are consistent.

## Example C. Age-adjusted Body Mass Index Among Mexican- American Women Age 20 and Older: National Health and Nutrition Examination Survey, 1999–2016

### Overview

This example demonstrates a case in which the test for a linear trend using SUDAAN is statistically significant, the test for a quadratic trend using SUDAAN is not statistically significant, the Joinpoint software suggests one joinpoint at the 2009–2010 survey cycle, and a piecewise regression in SUDAAN indicates that the change in the slopes between the two line segments around the 2009–2010 time point is statistically significant. In this case, the perceived inconsistency between step 2 and steps 3–4 are due to differences between modeling a nonlinear polynomial (quadratic) curve and modeling two linear line segments in a piecewise regression model.

### Step 1: Compute estimates for each survey cycle and plot the estimates

Weighted estimates and standard errors by survey cycle are presented in Table VI and Figure VIII.

Figure VIII Age-adjusted mean body mass index among Mexican-American women age 20 and older

NOTES: Body mass index (BMI) is calculated as weight in kilograms divided by height in meters squared (kg/m^2^). Age-adjusted mean BMI was obtained using record-level data and SUDAAN’s PROC DESCRIPT with mobile examination center weights and direct age-adjustment to the U.S. Census standard female population.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–2016.

Figure VIII is a scatterplot of the age-adjusted mean body mass index among Mexican-American women age 20 and older.

Table VI

Age-adjusted mean body mass index with standard errors, by survey cycle among Mexican-American women age 20 and older

Survey cycle | n | Mean (weighted) | Standard error
1999–2000 | 572 | 29.0 | 0.4
2001–2002 | 450 | 29.1 | 0.5
2003–2004 | 415 | 29.8 | 0.5
2005–2006 | 402 | 29.5 | 0.4
2007–2008 | 486 | 29.9 | 0.3
2009–2010 | 547 | 29.9 | 0.2
2011–2012 | 237 | 30.6 | 0.5
2013–2014 | 375 | 31.2 | 0.4
2015–2016 | 498 | 31.9 | 0.4

NOTES: Body mass index (BMI) is calculated as weight in kilograms divided by height in meters squared (kg/m^2^). Age-adjusted mean BMI was obtained using record-level data and SUDAAN’s PROC DESCRIPT with mobile examination center weights and direct age adjustment to the U.S. Census Bureau standard female population.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–2016.

### Step 2: Initial assessment of nonlinearity: Polynomial regression or orthogonal polynomial contrasts

Estimates with standard errors are presented in Table VII for the simple linear regression model and quadratic regression model.

Table VII

Linear and quadration regression estimates with standard errors of age-adjusted mean body mass index among Mexican-American women age 20 and older

Model | β_0_ (standard error) | β_1_ (standard error) | β_2_ (standard error) | β_3_ (standard error) | Linear and quadratic contrast
Model | β_0_ (standard error) | Age | Survey cycle | Survey cycle squared | Linear and quadratic contrast
Simple linear regression | 26.90 (0.42) | 0.77 (0.14) | 0.35 (0.06) | … | …
p values | < 0.0001 | < 0.0001 | < 0.0001 | … | < 0.0001
Quadratic regression | 27.73 (0.61) | 0.77 (0.13) | -0.06 (0.23) | 0.04 (0.02) | …
p values | < 0.0001 | < 0.0001 | 0.7830 | 0.0732 | 0.0824

… Category not applicable.

NOTES: Body mass index (BMI) is calculated as weight in kilograms divided by height in meters squared (kg/m^2^). Mean BMI estimates and standard errors were obtained using record-level data and SUDAAN’s PROC REGRESS with mobile examination center weights. Survey cycles 1999–2000 through 2015–2016 were coded as 1 through 9 for all regression analyses.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–2016.

### Step 3: Estimate the number and location of joinpoints for nonlinear trends using Joinpoint software

For this example, the following options were selected in the Joinpoint software:

1. Log transformation: No
2. Heteroscedastic/correlated errors option: Variance–covariance matrix (provided)
3. Method: Grid search
  a. Minimum number of observations from a joinpoint to either end of the data: Two
  b. Minimum number of observations between two joinpoints: Two
  c. Number of points to place between adjacent observed x values in the grid search: Zero
4. Number of joinpoints:
  a. Minimum: Zero
  b. Maximum: One
5. Model selection method: BIC (fewer than 10 time points).

Automated output from the Joinpoint software (graph and model estimates) are presented in Figure IX.

Figure IX Joinpoint software’s automated output: Age-adjusted mean body mass index among Mexican-American women age 20 and older

* Indicates that the slope is significantly different from zero at the α = 0.05 level. Final selected model has one joinpoint.

NOTES: Body mass index (BMI) is calculated as weight in kilograms divided by height in meters squared (kg/m^2^). Age-adjusted mean BMI was obtained using record-level data and SUDAAN’s PROC DESCRIPT with mobile examination center weights and direct age-adjustment to the U.S. Census standard female population. Survey cycles 1999–2000 through 2015–2016 were coded as 1 through 9 for all regression analyses.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–2016.

Figure IX is a scatterplot of the Joinpoint software’s automated output of the age-adjusted mean body mass index among Mexican-American women age 20 and older.

Test number | Null hypothesis | Alternate hypothesis | Degrees of freedom | | Number of permutations | p value | Significance level
Test number | Null hypothesis | Alternate hypothesis | Numerator | Denominator | Number of permutations | p value | Significance level
1 | 0 joinpoint(s) | 2 joinpoint(s) | 4 | 6 | 4500 | 0.0002222 | 0.025
2 | 1 joinpoint(s) | 2 joinpoint(s) | 2 | 6 | 4500 | 0.0031111 | 0.050

### Step 4: Obtain final slope estimates and tests of trend using a standard survey package

Because the Joinpoint software identifies a joinpoint at the 2009–2010 survey cycle (the sixth time point), a piecewise regression model was run in SUDAAN. This model also identified a statistically significant change in slopes at the 2009–2010 survey cycle. As a result, the piecewise regression model was chosen as the final model (Table VIII).

Table VIII

Final piecewise regression estimates with standard errors of age-adjusted mean body mass index among Mexican-American women age 20 and older

Model components | β (standard error) | p value
Intercept | 28.67 (0.43) | < 0.0001
1st line segment (1999–2000 through 2009–2010) | 0.18 (0.09) | 0.05
2nd line segment (2009–2010 through 2017–2018) | 0.65 (0.15) | < 0.0001
Change in slopes | 0.47 (0.20) | 0.02

NOTES: Body mass index (BMI) is calculated as weight in kilograms divided by height in meters squared (kg/m^2^). Mean BMI estimates and standard errors were obtained using record-level data and SUDAAN’s PROC REGRESS with age-adjusted mobile examination center weights. Survey cycles 1999–2000 through 2015–2016 were coded as 1 through 9 for all regression analyses.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–2016.

### Conclusions

Based on SUDAAN, the change in slopes for the piecewise model suggested by the Joinpoint software (with a joinpoint at the 2009–2010 survey cycle) is statistically significant (p = 0.02) (Table VIII). This coincides with the graphical depictions and subject matter expertise. Therefore, the best model for the data is the piecewise regression model (Figure X) indicating that age-adjusted mean body mass index among Mexican-American females increased at an average rate of 0.18 per survey cycle (about 0.09 per year) between 1999–2000 and 2009–2010 and at an average rate of 0.65 per survey cycle (about 0.32 per year) between 2009–2010 and 2017–2018.

Figure X Final piecewise regression model for age-adjusted body mass index among Mexican-American women ages 20 and older

NOTES: Body mass index (BMI) is calculated as weight in kilograms divided by height in meters squared (kg/m^2^). Mean BMI estimates and standard errors for the regression were obtained using record-level data and SUDAAN’s PROC REGRESS with age-adjusted mobile examination center weights. Survey cycles 1999–2000 through 2015–2016 were coded as 1 through 9 for all regression analyses. Piecewise regression model shown is presented in Table VIII in this report.

SOURCE: National Center for Health Statistics, National Health and Nutrition Examination Survey, 1999–2016.

Figure X is a scatterplot of the final piecewise regression model for age-adjusted body mass index among Mexican-American women ages 20 and older.

### Explanation of differences

In this case, the results from the linear and quadratic regressions in step 2 indicate a linear trend (Table VII), the results from the Joinpoint software suggest using a piecewise model (Figure IX), and the piecewise regression model in SUDAAN is statistically significant (Table VIII, Figure X). The perceived inconsistency between step 1 (statistically insignificant quadratic regression) and steps 3 and 4 (statistically significant piecewise regressions) are due to differences between modeling a nonlinear polynomial (quadratic) curve and modeling two linear line segments in a piecewise regression model.

## Example D. Percentage of U.S. Children Age 17 and Younger Who Had Private Health Insurance at the Time of Interview: National Health Interview Survey, 2007–2018

### Overview

This example demonstrates a case in which the tests for quadratic and cubic trends are both statistically significant and Joinpoint software suggests two joinpoints (2010 and 2013). However, when the piecewise regression model suggested by the Joinpoint software is fit in the R survey package, the change in slopes between segments two and three (at 2013) is not statistically significant. A piecewise regression in the R survey package with a single joinpoint at 2010 indicates a good fit and is chosen as the best model for the data. Data used in this example are from the IPUMS Health Surveys: National Health Interview Series (19).

### Step 1: Compute annual survey estimates and plot the estimates

Weighted percentage estimates and standard errors by survey cycle are presented in Table IX and Figure XI.

Figure XI Percentage of U.S. children age 17 and younger who had private health insurance at the time of interview

NOTES: Children were defined as having private health insurance if they had health insurance coverage and were covered by a private health insurance plan, defined as insurance other than Medicare, Medicaid, State Children's Health Insurance Plan (CHIP), state-sponsored health plans, other government programs, and military health plans (including TRICARE, VA, and Civilian Health and Medical Program of VA [CHAMP-VA]). These plans include those obtained through an employer, purchased directly, purchased through local or community programs, or purchased through the Health Insurance Marketplace or a state-based exchange. Private coverage excludes plans that pay for only one type of service, such as dental, vision, or prescription drugs.

SOURCE: National Center for Health Statistics, IPUMS Health Surveys, National Health Interview Survey, Family Core component version 7.3, 2007–2018.

Figure XI is a scatterplot of the percentage of U.S. children age 17 and younger who had private health insurance at the time of interview.

Table IX

Survey estimates and standard errors by year for the percentage of U.S. children age 17 and younger who had private health insurance at the time of interview

Year | n | Weighted percent | Standard error
2007 | 9,373 | 59.3 | 0.75
2008 | 8,766 | 57.9 | 0.77
2009 | 11,116 | 55.3 | 0.81
2010 | 11,243 | 53.8 | 0.76
2011 | 12,793 | 53.9 | 0.71
2012 | 13,210 | 53.5 | 0.71
2013 | 12,808 | 53.0 | 0.67
2014 | 13,325 | 53.5 | 0.69
2015 | 12,233 | 54.4 | 0.72
2016 | 11,049 | 54.5 | 0.76
2017 | 8,794 | 55.4 | 0.85
2018 | 8,234 | 55.3 | 0.91

NOTES: Children were defined as having private health insurance if Children were defined by a private health insurance plan, defined as insurance other than Medicare, Medicaid, state Children’s Health Insurance Plan (CHIP), state-sponsored health plans, other government programs, and military health plans (including TRICARE, VA, and Civilian Health and Medical Program of VA [CHAMP-VA]). These plans include those obtained through an employer, purchased directly, purchased through local or community programs, or purchased through the Health Insurance Marketplace or a state-based exchange. Private coverage excludes plans that pay for only one type of service, such as dental, vision, or prescription drugs.

SOURCE: National Center for Health Statistics, IPUMS Health Surveys, National Health Interview Survey, Family Core component version 7.3, 2007–2018.

### Step 2: Initial assessment of nonlinearity: Polynomial regression or orthogonal polynomial contrasts

Estimates with standard errors are presented in Table X for the simple linear regression model, quadratic regression model, and cubic regression model.

Table X

Linear, quadratic, and cubic regression estimates with standard errors for the percentage of U.S. children age 17 and younger who had private health insurance at the time of interview

Model | β_0_ (standard error) | β_1_ (standard error) | β_2_ (standard error) | β_3_ (standard error)
Model | Intercept | Year | Year squared | Year cubed
Linear regression | 56.35 | -0.25 | … | …
p values | < 0.0001 | 0.0030 | … | …
Quadratic regression | 58.93 | -1.80 | 0.14 | …
p values | < 0.0001 | < 0.0001 | < 0.0001 | …
Cubic regression | 59.65 | -2.81 | 0.38 | -0.01
p values | < 0.0001 | < 0.0001 | 0.0006 | 0.0277

… Category not applicable.

NOTES: Children were defined as having private health insurance if they had health insurance coverage and were covered by a private health insurance plan, defined as insurance other than Medicare, Medicaid, state Children’s Health Insurance Plan (CHIP), state-sponsored health plans, other government programs, and military health plans (including TRICARE, VA, and Civilian Health and Medical Program of VA [CHAMP-VA]). These plans include those obtained through an employer, purchased directly, purchased through local or community programs, or purchased through the Health Insurance Marketplace or a state-based exchange. Private coverage excludes plans that pay for only one type of service, such as dental, vision, or prescription drugs. The year variable was centered at 2007 (YEAR minus 2007) before running the polynomial regression.

SOURCE: National Center for Health Statistics, IPUMS Health Surveys, National Health Interview Survey, Family Core component version 7.3, 2007–2018.

### Step 3: Estimate the number and location of joinpoints for nonlinear trends using Joinpoint software

For this example, the following options were selected in the Joinpoint software:

1. Log transformation: No
2. Heteroscedastic/correlated errors option: Variance–covariance matrix (provided)
3. Method: Grid search
  a. Minimum number of observations from a joinpoint to either end of the data: Two
  b. Minimum number of observations between two joinpoints: Two
  c. Number of points to place between adjacent observed x values in the grid search: Zero
4. Number of joinpoints:
  a. Minimum: Zero
  b. Maximum: Two
5. Model selection method: Permutation test (10 or more time points).

Automated output from the Joinpoint software (graph and model estimates) are presented in Figure XII.

Figure XII Joinpoint software’s automated output: Percentage of U.S. children age 17 and younger who had private health insurance at the time of interview* Indicates that the slope is significantly different from zero at the α = 0.05 level. Final selected model has two joinpoints.

NOTES: Children were defined as having private health insurance if they had health insurance coverage and were covered by a private health insurance plan, defined as insurance other than Medicare, Medicaid, State Children's Health Insurance Plan (CHIP), state-sponsored health plans, other government programs, and military health plans (including TRICARE, VA, and Civilian Health and Medical Program of VA [CHAMP-VA]). These plans include those obtained through an employer, purchased directly, purchased through local or community programs, or purchased through the Health Insurance Marketplace or a state-based exchange. Private coverage excludes plans that pay for only one type of service, such as dental, vision, or prescription drugs.

SOURCE: National Center for Health Statistics, IPUMS Health Surveys, National Health Interview Survey, Family Core component version 7.3, 2007–2018.

Figure XII is a scatterplot of the Joinpoint software’s automated output of the percentage of U.S. children age 17 and younger who had private health insurance at the time of interview.

Model | Number of joinpoints | Number of observations | Number of parameters | Degrees of freedom | Sum of squared errors | BIC
1 | 0 joinpoint(s) | 9 | 2 | 7 | 8.0725392 | 0.3795156
2 | 1 joinpoint(s) | 9 | 4 | 5 | 1.2228318 | -1.019511

### Step 4: Obtain final slope estimates and tests of trend using a standard survey package

Estimates with standard errors for the prespecified piecewise regression model recommended by the Joinpoint software and estimated using the R survey package are presented in Table XI. Estimates with standard errors for the final piecewise regression model estimated using the R survey package are presented in Table XII and Figure XIII.

Figure XIII Final piecewise regression model for the percentage of U.S. children age 17 and younger who had private health insurance at the time of interview compared with the piecewise regression model recommended by the Joinpoint software

NOTES: Children were defined as having private health insurance if they had health insurance coverage and were covered by a private health insurance plan, defined as insurance other than Medicare, Medicaid, State Children's Health Insurance Plan (CHIP), state-sponsored health plans, other government programs, and military health plans (including TRICARE, VA, and Civilian Health and Medical Program of VA [CHAMP-VA]). These plans include those obtained through an employer, purchased directly, purchased through local or community programs, or purchased through the Health Insurance Marketplace or a state-based exchange. Private coverage excludes plans that pay for only one type of service, such as dental, vision, or prescription drugs. Piecewise regression models shown are presented in Tables XI and XII in this report. The year variable was centered at 2007(YEAR-2007) before running the piecewise regression analyses.

SOURCE: National Center for Health Statistics, IPUMS Health Surveys, National Health Interview Survey, Family Core component version 7.3, 2007–2018.

Figure XIII is a scatterplot of the final piecewise regression model for the percentage of U.S. children age 17 and younger who had private health insurance at the time of interview compared with the piecewise regression model recommended by the Joinpoint software.

Table XI

Model recommended by Joinpoint software: Piecewise regression estimates with standard errors for the percentage of U.S. children age 17 or younger who had private health insurance at the time of interview

Model component | β (standard error) | p value
Intercept | 59.42 (0.69) | < 0.0001
1st line segment (2007–2010) | -1.86 (0.30) | < 0.0001
2nd line segment (2010–2013) | -0.21 (0.24) | 0.3760
3rd line segment (2013–2018) | 0.47 (0.22) | 0.0349
Change in slopes (1st line segment to 2nd line segment) | 1.65 (0.48) | 0.0006
Change in slopes (2nd line segment to 3rd line segment) | 0.68 (0.39) | 0.0847

NOTES: Children were defined as having private health insurance if they had health insurance coverage and were covered by a private health insurance plan, defined as insurance other than Medicare, Medicaid, state Children’s Health Insurance Plan (CHIP), state-sponsored health plans, other government programs, and military health plans (including TRICARE, VA, and Civilian Health and Medical Program of VA [CHAMP-VA]). These plans include those obtained through an employer, purchased directly, purchased through local or community programs, or purchased through the Health Insurance Marketplace or a state-based exchange. Private coverage excludes plans that pay for only one type of service, such as dental, vision, or prescription drugs. The year variable was centered at 2007 (YEAR minus 2007) before running the piecewise regression.

SOURCE: National Center for Health Statistics, IPUMS Health Surveys, National Health Interview Survey, Family Core component version 7.3, 2007–2018.

Table XII

Final model: Piecewise regression estimates with standard errors for the percentage of U.S. children age 17 or younger who had private insurance at the time of interview

Component | β (standard error) | p value
Intercept | 59.59 (0.68) | < 0.0001
1st line segment (2007–2010) | -2.11 (0.29) | < 0.0001
2nd line segment (2010–2018) | 0.22 (0.13) | 0.0816
Change in slopes (1st line segment to 2nd line segment) | 2.33 (0.37) | < 0.0001

NOTES: Children were defined as having private health insurance if they had health insurance coverage and were covered by a private health insurance plan, defined as insurance other than Medicare, Medicaid, state Children’s Health Insurance Plan (CHIP), state-sponsored health plans, other government programs, and military health plans (including TRICARE, VA, and Civilian Health and Medical Program of VA [CHAMP-VA]). These plans include those obtained through an employer, purchased directly, purchased through local or community programs, or purchased through the Health Insurance Marketplace or a state-based exchange. Private coverage excludes plans that pay for only one type of service, such as dental, vision, or prescription drugs. The year variable was centered at 2007 (YEAR minus 2007) before running the piecewise regression.

SOURCE: National Center for Health Statistics, IPUMS Health Surveys, National Health Interview Survey, Family Core component version 7.3, 2007–2018.

### Conclusions

Based on the R survey package, the change in slopes at 2010 (p = 0.0006) is statistically significant, while the change in slopes at 2013 (as suggested by the Joinpoint software) is not statistically significant (p = 0.0847). As a result, the best model for the data is the piecewise regression model (Table XII, Figure XIII) indicating that the percentage of U.S. children age 17 and younger who had private health insurance at the time of the interview decreased at an average rate of 2.11% (p < 0.0001) per year between 2007 and 2010 and then remained relatively steady between 2010 and 2018.

### Explanation of differences

In this example, the tests for quadratic and cubic trends are both statistically significant (Table X) and the Joinpoint software suggests two joinpoints (2010 and 2013, Figure XII). However, when the piecewise regression model suggested by the Joinpoint software is fit in the R survey package, the change in slopes between segments two and three (at 2013) is not statistically significant (Table XI). In this case, the inconsistency between steps 1–3 and step 4 are likely due to differences in the model selection criterion for the BIC test (the Joinpoint software) versus the segment-wise t test (R survey package); BIC uses the entire time series, while the segment-wise testing uses only segment-specific observations.