# Front Matter

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Research and Methodology

Morgan S. Earp, Ph.D., Acting Director

John R. Pleis, Ph.D., Associate Director for Science

Division of Analysis and Epidemiology

Irma E. Arispe, Ph.D., Director

Kimberly A. Lochner, Sc.D., Associate Director for Science

Division of Health and Nutrition Examination Surveys

Alan E. Simon, M.D., Director

Lara J. Akinbami, M.D., Associate Director for Science

Division of Health Interview Statistics

Stephen J. Blumberg, Ph.D., Director

Anjel Vahratian, Ph.D., M.P.H., Associate Director for Science

## Acknowledgments

The authors gratefully acknowledge Barnali Das, Donald J. Malec (retired), Kimberly Daniels, and Margaret Carroll from the National Center for Health Statistics (NCHS) for their contributions to this report.

Kate Hubbard and Deanna Kruszon-Moran were employed at NCHS’s Division of Analysis and Epidemiology and Division of National Health and Nutrition Examination Surveys, respectively, when this work with the Division of Analysis and Epidemiology was conducted. Makram Talih completed this work with the Division of Analysis and Epidemiology under a contract from Windsor Group, LLC.