# References

1 Rubin DB. Discussion: Statistical disclosure limitation. J Off Stat. 1993;9:461–8.
2 Raghunathan TE, Reiter JP, Rubin DB. Multiple imputation for statistical disclosure limitation. J Off Stat. 2003;19(1):1–16.
3 Matthews GJ, Harel O. Data confidentiality: A review of methods for statistical disclosure limitation and methods for assessing privacy. Stat Surv. 2011;5:1–29.
4 Hundepool A, Domingo-Ferrer J, Franconi L, Giessing S, Nordholt ES, Spicer K, de Wolf P. Statistical disclosure control. John Wiley & Sons. 2012.
5 Fuller W. Masking procedures for microdata disclosure limitation. J Off Stat. 1993;9:383–406.
6 Dalenius T, Reiss SP. Data-swapping: A technique for disclosure control. J Stat Plan Inference. 1982;6:73–85.
7 Reiter JP. Satisfying disclosure restriction with synthetic data sets. J Off Stat. 2002;18(4):531–43.
8 Reiter JP. Inference for partially synthetic, public use microdata sets. Surv Methodol. 2003;29(2):181–8.
9 Little RJA. Statistical analysis of masked data. J Off Stat. 1993;9:407–26.
10 Fienberg SE, Steele RJ. Disclosure limitation using perturbation and related methods for categorical data. J Off Stat. 1998:14(4):485–502.
11 Drechsler J. Synthetic datasets for statistical disclosure control: Theory and implementation. Vol. 201. Springer Science & Business media. 2011.
12 Gouweleeuw JM, Kooiman P, Wolf P. Post randomisation for statistical disclosure control: Theory and implementation. J Off Stat. 1998;14(4):463.
13 Moore R Jr. Controlled data-swapping techniques for masking public use microdata. Census Tech Report. 1996. Available from: https://www.census.gov/content/dam/Census/library/working-papers/1996/adrm/rr96-4.pdf.
14 Oganian A, Karr AF. Combinations of SDC methods for microdata protection. In: Domingo-Ferrer J, Franconi L, editors. Privacy in statistical databases. Springer Berlin Heidelberg. 2006. p. 102–113.
15 Reiter JP. Estimating risks of identification disclosure in microdata. J Am Stat Assoc. 2005;100:1103–12.
16 Irimata KE, He Y, Cai B, Shin H-C, Parsons VL, Parker JD. Comparison of quarterly and yearly calibration data for propensity score adjusted web survey estimates. Surv Methods Insights Field. Special issue: Advancements in online and mobile survey methods. 2020. DOI: 10.13094/SMIF-2020-00018.
17 Parker J, Miller K, He Y, Scanlon P, Cai B, Shin H-C, et al. Overview and initial results of the National Center for Health Statistics’ Research and Development Survey. Stat J IAOS. 2020;6(4):1199–1211. DOI: 10.3233/SJI-200678.
18 He Y, Cai B, Shin H-C, Beresovsky V, Parsons V, Irimata K, et al. The National Center for Health Statistics’ 2015 and 2016 Research and Development Surveys. Vital Health Stat 1(64). 2020. Available from: https://www.cdc.gov/nchs/data/series/sr_01/sr01-64-508.pdf.
19 National Center for Health Statistics. RANDS during COVID-19 round 3 technical documentation. Hyattsville, Maryland. 2022. Available from: https://archive.cdc.gov/www_cdc_gov/nchs/rands/files/RANDS_COVID_3_technical_documentation.pdf.
20 Raghunathan TE, Solenberger P, Berglund P, Hoewyk JV. IVEware: Imputation and variance estimation software (Version 0.3). 2016.
21 Nowok B, Raab GM, Dibben C. Synthpop: Bespoke creation of synthetic data in R. J Stat Softw. 2016;74(11):1–26. DOI: 10.18637/jss.v074.i11.
22 Reiter JP. Using CART to generate partially synthetic public use microdata. J Off Stat. 2005;21(3):441–462.
23 Drechsler J, Reiter J. An empirical evaluation of easily implemented, nonparametric methods for generating synthetic datasets. Comput Stat Data Anal. 2011;55:3232–3243.
24 Reiter JP. Simultaneous use of multiple imputation for missing data and disclosure limitation. Surv Methodol. 2004;30(2):235–242.
25 SAS Institute Inc. SAS® 9.4 language reference: Concepts, sixth edition. Cary, NC: SAS Institute Inc. 2016.
26 Reiter JP. Significance tests for multi-component estimands from multiply imputed, synthetic microdata. J Stat Plan Inference. 2005;131:365–77.
27 Karr A, Kohnen CN, Oganian A, Reiter JP, Sanil AP. A framework for evaluating the utility of data altered to protect confidentiality. Am Stat. 2006;60(3):224–32.
28 Snoke J, Raab GM, Nowok B, Dibben C, Slavkovic A. General and specific utility measures for synthetic data. J R Stat Soc Ser A Stat Soc. 2018;181(3):663–88. DOI: 10.1111/rssa.12358.
29 Woo MJ, Reiter JP, Oganian A, Karr AF. Global measures of data utility for microdata masked for disclosure limitation. J Priv Confid. 2009;1(1). DOI: 10.29012/jpc.v1i1.568.
30 Reiter JP, Wang Q, Zhang B. Bayesian estimation of disclosure risks for multiply imputed, synthetic data. J Priv Confid. 2014;6(1). DOI: 10.29012/jpc.v6i1.635.
31 Paiva T, Chakraborty A, Reiter J, Gelfand A. Imputation of confidential data sets with spatial locations using disease mapping models. Stat Med. 2014;33(11):1928–45. DOI: 10.1002/sim.6078.24395116
32 Reiter JP and Mitra R. Estimating risks of identification disclosure in partially synthetic data. J Priv Confid. 2009;1(1). DOI: 10.29012/jpc.v1i1.567.