# Discussion

Synthetic data is a promising method to balance the need for keeping data utility and protecting privacy for public-use data. However, generating synthetic data for national surveys is challenging because of complex survey designs, high dimensionality of the original data with different distributional forms, and complicated data structures. This report focused on incorporating survey design information during the synthetic data-generating process.

Three approaches incorporating survey design information to create synthetic data using both parametric and nonparametric methods were compared. The nonparametric method (CART) yielded better data utility than the parametric methods in Approaches 1 and 2, where all or part of the survey design information was synthesized along with the analytical variables. When none of the design information was synthesized (Approach 3), both the parametric and nonparametric methods yielded similar data utility. The poorer performance of Approaches 1 and 2 using the parametric method might be related to the unusual data format of the survey design information, the sampling weights, which was a truncated continuous variable. The parametric method was sensitive to the underlying model assumptions, and violation of model assumptions would create synthetic values dissimilar to the original data, leading to low CI overlap. On the other hand, the nonparametric method (CART) was more robust for unusual data types, and synthesizing the survey design information did not lead to low data utility. Keeping original survey design variables while using them as covariates to synthesize the analytical variables (Approach 3) helped data utility for the parametric approach, with data utility measurements improved to the level of the nonparametric method.

Although the nonparametric method yielded better data utility, it also increased disclosure risk. The disclosure risk was related to the amount of information to be synthesized (or not synthesized). In this study, it was related to whether the survey design information was used as predictors (instead of being synthesized). The more the survey design information was used as predictors, the higher the chance of creating synthesized records identical to the original data, leading to a higher disclosure risk. The mean matching probabilities were higher in Approach 3 than in Approaches 1 and 2 for both the nonparametric method (CART) and the parametric method using the R synthpop package. However, unlike the parametric method, synthesizing survey design information using the nonparametric method impacted more on disclosure risk but less on data utility because the nonparametric method was less sensitive to unusual data types of survey design information. Thus, synthesizing survey design information using the nonparametric method may be an option to balance the trade-off between data utility and disclosure risk. Moreover, applying parametric and nonparametric methods according to different data types should be used to achieve optimal data utility and disclosure risk.