# Results

## Results of CI Overlap

Table 3 shows the means of CI overlap across all synthesized analytical variables. Synthesizing survey design information during data synthesis reduced data utility, but the impact was only shown in the parametric method. For Approach 1, where all survey design information was synthesized, the parametric method implemented using the R synthpop package yielded a mean CI overlap of 0.73, while the nonparametric method yielded a mean CI overlap of 0.88. For Approach 2, where design variables were not synthesized but the sampling weights were synthesized, using the square root transformation on the sampling weights (R synthpop) or using the bounds function for the sampling weights (IVEware) yielded similar means of CI overlap (0.71 and 0.70, respectively); the nonparametric method yielded a mean CI overlap of 0.89. For Approach 3, where none of the survey design information was synthesized, the two parametric methods yielded results (0.88 using the R synthpop package, 0.85 using IVEware) close to the nonparametric method (0.88 using the R synthpop package).

Table 3

Mean of confidence interval overlap across all synthesized analytical variables: Research and Development Survey During COVID-19, Round 3

Method | Software used for implementation | Approach 1^1^ | Approach 2^2^ | Approach 3^3^
Parametric | R synthpop (regression) | 0.73 | 0.71 | 0.88
Parametric | IVEware (SYNTHESIZE) | … | 0.70 | 0.85
Nonparametric | R synthpop (CART^4^) | 0.88 | 0.89 | 0.88

… Category not applicable.

1 All variables synthesized.

2 Design variables not synthesized, weights synthesized.

3 Design variables and weights not synthesized.

4 Classification and regression trees.

SOURCE: National Center for Health Statistics, Research and Development Survey During COVID-19 Round 3, 2021.

## Results of Propensity Score Measurement

The means of the estimated propensity scores and the range of the propensity scores are in Table 4. The means of the propensity scores for all three approaches were the same (0.50) using either the nonparametric method or the parametric method using the R synthpop package. The means of the propensity scores from the parametric method using IVEware differed more from 0.50 compared with the other methods (0.56 for Approach 2 and 0.51 for Approach 3). The estimated propensity scores would be close to 0.50 for all records if the original and synthetic data had similar distributions. Thus, a narrower range around 0.50 suggests the two data sets are closer. In this analysis, the ranges of the propensity scores were narrower for the nonparametric method compared with the parametric methods (IVEware was not applied to Approach 1). For example, for Approach 1, the range of the propensity scores was 0.42 to 0.61 for the nonparametric method (CART in R), while the range of the propensity scores was 0.34 to 0.70 for the parametric method (regression in R). Similar patterns were shown in Approaches 2 and 3. The results suggested that the distributions of the synthetic data created from the nonparametric method were closer to the distributions of original data than those created from the parametric methods, especially in Approaches 1 and 2.

Table 4

Propensity scores estimated from a weighted logistic regression model: Research and Development Survey During COVID-19, Round 3

Method | Software used for implementation | Approach 1^1^ | Approach 2^2^ | Approach 3^3^
| | Mean (range)
Parametric | R synthpop (regression) | 0.50 (0.34–0.70) | 0.50 (0.35–0.64) | 0.50 (0.42–0.64)
Parametric | IVEware (SYNTHESIZE) | … | 0.56 (0.45–0.68) | 0.51 (0.40–0.64)
Nonparametric | R synthpop (CART^4^) | 0.50 (0.42–0.61) | 0.50 (0.41–0.56) | 0.50 (0.42–0.57)

… Category not applicable.

1 All variables synthesized.

2 Design variables not synthesized, weights synthesized.

3 Design variables and weights not synthesized.

4 Classification and regression trees.

SOURCE: National Center for Health Statistics, Research and Development Survey During COVID-19 Round 3, 2021.

## Results of Sampling Weight Comparisons From Approach 2

For Approach 2, with the parametric method, the only difference between the R synthpop package and the IVEware was how the continuous variable, the sampling weights, was synthesized. If the original and synthetic data were similar, the distributions of the original and synthesized sampling weights would be close to each other. In this analysis, quantiles and means of the original and synthetic sampling weights were compared (Table 5). The range of the original sampling weights was from 0.01 to 17.65. The parametric methods yielded a narrower range of the sampling weights using both the R synthpop package and the IVEware SYNTHESIZE module (0.00 [rounded] to 5.25 and 0.00 [rounded] to 5.34 for R and IVEware, respectively). In contrast, the range of the synthesized sampling weights using the nonparametric method was about the same as that of the original data. The quantiles of the sampling weights using the parametric methods departed from the original data, while the quantiles of sampling weights using the nonparametric method were closer to those of the original data. The differences in the synthesized sampling weights led to better performance of the nonparametric method (R CART), including a higher mean of CI overlap and a narrower range of propensity score measurements, compared with the parametric methods (Tables 3 and 4). For the parametric methods, although the ranges of the synthesized sampling weights were similar using IVEware and R, the mean and median of the synthesized sampling weights using R (regression) were closer to those of the original data than those using IVEware (mean: 1.27, 1.00, and 1.00 for IVEware, R, and the original data, respectively; median: 1.15, 0.83, 0.69 for IVEware, R, and the original data, respectively), which corresponded to a mean of propensity scores higher than 0.50 using IVEware for Approach 2 (Table 4).

Table 5

Quantiles and means of the original and synthesized sampling weights for selected parametric and nonparametric synthesis methods applied to Approach 2: Research and Development Survey During COVID-19, Round 3

Quantile | Original data | Parametric method | | Nonparametric method
Quantile | Original data | R | IVEware | R
100% maximum | 17.65 | 5.25 | 5.34 | 17.65
99% | 5.12 | 3.60 | 3.52 | 4.70
95% | 2.86 | 2.57 | 2.80 | 2.86
90% | 2.12 | 2.07 | 2.39 | 2.05
75% | 1.24 | 1.42 | 1.79 | 1.23
50% median | 0.69 | 0.83 | 1.15 | 0.68
25% | 0.37 | 0.39 | 0.61 | 0.36
10% | 0.22 | 0.14 | 0.26 | 0.22
5% | 0.14 | 0.05 | 0.14 | 0.14
1% | 0.05 | 0.00^1^ | 0.03 | 0.05
0% minimum | 0.01 | 0.00^2^ | 0.00^3^ | 0.01
Mean | 1.00 | 1.00 | 1.27 | 0.98

1 Rounded to 0.00 from 0.002.

2 Rounded to 0.00 from 0.00000002.

3 Rounded to 0.00 from 0.001.

NOTE: Approach 2 is design variables not synthesized.

SOURCE: National Center for Health Statistics, Research and Development Survey During COVID-19, Round 3.

## Disclosure Risk Analysis via Average Matching Probability

Five target cases were selected based on the number of records with identical information (records with the same age, sex, education, etc., across all 12 analytical variables) (Table 6). For example, the first target case was a sample unique case (no other record with the same values across all 12 variables as the target case was seen in the original data); and the last target case is a case where there were 20 subjects in the original data with identical measurements across the 12 analytical variables. For each target case, the intruder is assumed to know only the values of four variables: age, race and ethnicity, education, and sex. Linking these four variables to the synthetic data, the intruder would be able to identify cases with identical values for the four variables, although the linked cases may or may not be a true match.

Table 6

Average matching probability of Approach 1, by selected synthesis method and number of records with matching original values: Research and Development Survey During COVID-19, Round 3

Target case | Records with the same values in the original data | Parametric | | Nonparametric
Target case | Records with the same values in the original data | R (regression) | IVEware (regression) | R (CART^1^)
| Number | Percent
1 | 1 (unique record in the original data) | 0.29 | … | –
2 | 5 | 1.11 | … | 0.94
3 | 10 | 4.16 | … | 4.29
4 | 15 | 2.62 | … | 3.70
5 | 20 (high frequency record in the original data) | 4.53 | … | 5.79
Across all target cases | Mean | 2.54 | … | 2.94

… Category not applicable.

– Quantity zero.

1 Classification and regression trees.

NOTE: Approach 1 is all variables synthesized.

SOURCE: National Center for Health Statistics, Research and Development Survey During COVID-19, Round 3.

Table 6 shows the matching probability of each target case and the mean matching probability (expressed as percentages) across the five target cases for Approach 1. The parametric method implemented using R synthpop had a low matching probability when the target case was a unique sample record (0.29% for target case 1) or when there was a small number of records with identical values (1.11% for target case 2). When the number of records with values identical to the target case increased (10 or more records with identical values in the original data), the matching probability of the parametric method also increased (4.16%, 2.62%, and 4.53% for target cases 3–5, respectively). Similar patterns were shown in the nonparametric method. However, the increasing trend was not monotone, because when Nmatch_i_ increased in the synthetic data, "n_i_" also tended to increase. Thus, the matching probability decreased for target case 4 (15 records with identical information in the original data) and then increased for target case 5 (20 records with identical information in the original data) for both the parametric and nonparametric methods. The mean matching probability was slightly higher for the nonparametric method than the parametric method (2.94 compared with 2.54). Approaches 2 and 3 showed a similar pattern as Approach 1 (Tables 7 and 8).

Table 7

Average matching probability of Approach 2, by selected synthesis method and number of records with matching original values: Research and Development Survey During COVID-19, Round 3

Target case | Records with the same values in the original data | Parametric | | Nonparametric
Target case | Records with the same values in the original data | R (regression) | IVEware (regression) | R (CART^1^)
| Number | Percent
1 | 1 (unique record in the original data) | 0.31 | 0.52 | –
2 | 5 | 1.42 | 1.16 | 0.68
3 | 10 | 3.44 | 3.75 | 5.06
4 | 15 | 3.72 | 2.72 | 4.45
5 | 20 (high frequency record in the original data) | 5.22 | 4.83 | 5.38
Across all target cases | Mean | 2.82 | 2.60 | 3.11

– Quantity zero.

1 Classification and regression trees.

NOTE: Approach 2 is design variables not synthesized.

SOURCE: National Center for Health Statistics, Research and Development Survey During COVID-19, Round 3.

Table 8

Average matching probability of Approach 3, by selected synthesis method and number of records with matching original values: Research and Development Survey During COVID-19, Round 3

Target case | Records with the same values in the original data | Parametric | | Nonparametric
Target case | Records with the same values in the original data | R (regression) | IVEware (regression) | R (CART^1^)
| Number | Percent
1 | 1 (unique record in the original data) | 0.82 | – | –
2 | 5 | 0.94 | 1.09 | 1.78
3 | 10 | 4.37 | 3.78 | 4.29
4 | 15 | 3.25 | 3.14 | 3.89
5 | 20 (high frequency record in the original data) | 5.66 | 4.01 | 6.22
Across all target cases | Mean | 3.01 | 2.40 | 3.24

– Quantity zero.

1 Classification and regression trees.

NOTE: Approach 3 is design variables and weights not synthesized.

SOURCE: National Center for Health Statistics, Research and Development Survey During COVID-19, Round 3.

Although IVEware performed worse than the R synthpop package regarding data utility and propensity score measurement, the overall matching probability based on IVEware was the lowest for Approaches 2 and 3 (2.60% and 2.40%, respectively, for IVEware; 2.82% and 3.01%, respectively, for the R synthpop package using the parametric method; and 3.11% and 3.24%, respectively, for the R synthpop package using the nonparametric method) (Tables 7 and 8). The results of the disclosure risk analysis were in alignment with the trade-off between data utility and disclosure risk.