# Methods

## A General Procedure to Create Synthetic Data

To create synthetic data, the joint distribution of the variables to be synthesized can be estimated using a series of sequential conditional distributions. Let Y_1_, Y_2_, …, Y_k_ denote k variables to be synthesized, and let X denote a vector of variables not to be synthesized but to be used as predictors when synthesizing Y_1_, Y_2_, …, Y_k_. The synthesis process for Y_1_, Y_2_, …, Y_k_ is based on the following conditional distributions: f_1_(Y_1_|X), f_2_(Y_2_|Y_1_, X), …, f_k_(Y_k_|Y_1_, Y_2_, …, Y_k−1_, X). If X is empty, the variable to be synthesized first, Y_1_, can be generated by random sampling with replacement from the marginal distribution of Y_1_, f_1_(Y_1_), estimated from the original data.

## Incorporate Survey Design Information to Create Synthetic RANDS Data

RANDS During COVID-19 collected data on loss of work, use of telemedicine, and access to health care during the COVID-19 pandemic (for more information, see: https://www.cdc.gov/nchs/covid19). Table 1 shows the selected demographic and health variables from RANDS During COVID-19 Round 3 for data synthesis. Variables that were common across all rounds of RANDS and had lower percentages of missing data were selected. The statistical inference of these variables (analytical variables) is used to evaluate different synthetic methods. For sample survey data such as RANDS, the survey design information, which includes strata, PSUs, and sampling weights, is an essential part of the survey. The design variables (strata and PSUs) are used to create meaningful subgroups and select representative units from the population. The sampling weights account for differences in selection probabilities and nonresponse rates and adjust for under- or over-representing specific groups within the sample. Using the sampling weights ensures that the estimates accurately represent the characteristics of the population. Both design variables and weights must be used for statistical analyses to derive valid variance and point estimates.

Table 1

Analytical variables selected for data synthesis: Research and Development Survey During COVID-19, Round 3

RANDS variable name | Definition | Category
AGE | Age | 1 is 18–44 2 is 45–64 3 is 65 and older
RACETHNICITY | Race and ethnicity | 1 is White, non-Hispanic 2 is Black, non-Hispanic 3 is Other, non-Hispanic 4 is Hispanic
EDUC | Education | 1 is High school graduate or less 2 is Some college 3 is Bachelor’s degree or more
Sex | Sex | 1 is Male 2 is Female
MARITAL | Marital status | 1 is Married 2 is Widowed 3 is Divorced 4 is Separated 5 is Never married 6 is Living with partner
REGION4 | Census region | 1 is Northeast 2 is Midwest 3 is South 4 is West
INCOME | Household income from the last year | 1 is Less than $50,000 2 is $50,000 to $99,999 3 is $100,000 or more
PHSTAT | Self-reported health status | 1 is Excellent, very good, good 2 is Fair, poor
HYPEV | Ever had doctor-diagnosed hypertension | 1 is Yes 2 is No
HICOV | Are you covered by any kind of health insurance or some other kind of health care plan? | 1 is Yes 2 is No
EMPLASTWK | Last week, did you work for pay at a job or business? | 1 is Yes 2 is No
SMKEV/SMKNOW | Current smoking status | 1 is Yes 2 is No

SOURCE: National Center for Health Statistics, Research and Development Survey During COVID-19 Round 3, 2021.

This research compared three approaches to incorporate survey design information in creating synthetic data. Approach 1 included design variables and sampling weights during the data synthesis process (variables were synthesized along with the analytical variables) (Table 1). Approach 2 synthesized the sampling weights along with the analytical variables during the synthesis process. While the design variables were not synthesized, they were used as predictors when synthesizing other variables. Approach 3 synthesized only the analytical variables without synthesizing any design variables or weights; however, the design variables and weights were used as predictors when synthesizing the analytic variables. Table 2 shows whether the design information was synthesized, and for which components, during the data synthesis process for Approaches 1–3.

Table 2

Role of design variables during the data synthesis process for Approaches 1–3: Research and Development Survey During COVID-19, Round 3

| Are any of the design variables (strata, PSU^1^) or sampling weights synthesized? | Which components of design information were synthesized? | Is all design information used as covariates when synthesizing the analytical variables?
Approach 1^2^ | Yes | Strata, PSU, sampling weights | Yes
Approach 2^3^ | Yes | Sampling weights | Yes
Approach 3^4^ | No | None | Yes

1 Primary sampling unit.

2 All variables synthesized.

3 Design variables not synthesized.

4 Design variables and weights not synthesized.

SOURCE: National Center for Health Statistics, Research and Development Survey During COVID-19 Round 3, 2021.

The joint distribution of the variables to be synthesized (the analytical variables in Table 1 and the survey design information in Table 2) can be estimated using a series of sequential conditional distributions described above. Both parametric and nonparametric methods can be used to estimate these conditional distributions. In this report, the performances of both methods were compared. For this analysis, the parametric method included a logistic or multinomial logistic model for categorical variables and a linear regression for continuous variables, implemented using the IVEware SYNTHESIZE module (20) and the R synthpop package (21). The nonparametric method included classification and regression trees (CART) methods, implemented using the R synthpop package (21–23). In CART, data are grouped into smaller homogeneous clusters by binary recursive partitioning of the predictors. At each partitioning step, a predictor and a split point are chosen, and all or a portion of the data set is split into two groups based on the split point of the predictor. This process repeats until a predetermined best-fit criterion, such as the residual sum of squares or deviance, is achieved. Then an observed value is drawn using simple random sampling from the final clusters as the synthetic value.

Both the R synthpop package and the IVEware SYNTHESIZE module were created for data synthesis purposes, and they both have multiple modeling options to create synthetic data. In this report, these two software packages were used for the parametric method so that the results from the two packages can be compared. For example, when the two packages used the same regression models, the results from both were expected to be similar. Consequently, a comparison of the results can serve as a model check. In addition, different modeling options can be used for the continuous sampling weights. In this study, the square root transformation was used for R, and the bounds function, a feature only available in IVEware that draws values from truncated predictive distributions, was used for IVEware; both options guaranteed that the synthesized sampling weights would be positive values.

The order of the variables to be synthesized affects data synthesis. Because the categorical variable strata had 71 levels, it needed to be the first to be synthesized by simple random sampling with replacement from the marginal distributional of strata, estimated from the original data. IVEware does not have this option. Instead, it synthesizes strata from a multinomial logistic regression model, which does not perform well for categorical variables with many categories, so IVEware was not applied to Approach 1. Thus, this study synthesized the design variables before the analytical variables (Approach 1 using R and Approach 2 using R and IVEware), and the order to synthesize the design variables is strata, PSUs (a variable nested within strata), and then sampling weights. All analytical variables included in this study were categorical variables with 2 to 6 levels, where logistic and multinomial logistic regression models perform well for the parametric approach. Without special patterns among these analytical variables (such as nested data structures or skip patterns), the storage order of the variables in the data set was used to synthesize them.

## Analysis of the Synthesized Data

For each approach described above, five synthetic data sets were created. Marginal proportions of all the analytic variables were derived for each synthetic data set, and survey design features were incorporated for variance estimation. For Approach 1, the synthesized design variables and sampling weights were used in the statistical analysis; for Approach 2, the original design variables and synthesized sampling weights were used in the analysis; and for Approach 3, the original design variables and sampling weights were used in the analysis. Results from each of the five synthetic data sets were combined using the combining rules of multiple synthetic data sets described later in this report (2,8,24). Statistical analyses were conducted using SAS (25).

## The combining rules of multiple synthetic data sets

Let Q be a parameter of interest (for example, population mean, proportion, regression coefficients, etc.), let q_i_ be the point estimate of Q, and u_i_ be its estimated variance from the ith synthetic data, where i = 1, 2, …, m, where m is the total number of synthetic data sets. The combined point estimate from the multiple synthetic data sets, q^ , is

q^ = (1)/(m) ∑_i = 1_^m^ q_i_ Actual text: q hat equals the quantity 1 over m times the quantity sum of q subscript i, from i equals 1 to m.

The estimated variance of this point estimate consists of two components. The first component, “within synthetic variance,” is the mean of variances across multiple synthetic data sets:

u¯ = (1)/(m) ∑_i = 1_^m^ u_i_ Actual text: u bar equals the quantity 1 over m times the quantity sum of u subscript i, from i equals 1 to m.

The second component, “between-synthetic variance,”

b¯ = (1)/(m − 1) ∑_i = 1_^m^ ( q_i_ − q^ )^2^ Actual text: b bar equals the quantity 1 over the quantity m minus 1 times the quantity sum of square of the quantity q subscript i minus q hat, from i equals 1 to m.

is the variation due to differences across m sets of synthetic data. The total estimated variance of the point estimate

V^ = u¯ + b¯ / m Actual text: V hat equals u bar plus the quantity b bar over m.

Furthermore, it was shown in Reiter (26) that, approximately,

( q^ − Q ) ~ t_d f_ ( 0 , V^ ) Actual text: q hat minus capital Q follows a t distribution with parameters 0 and V hat and a degree of freedom df.

where the degrees of freedom (df ) is

d f = ( m − 1 ) ( 1 + u¯ / ( b¯ / m ) )^2^ Actual text: df equals the quantity m mins 1 times the square of the quantity 1 plus the quantity u bar over the quantity b bar over m.

Confidence intervals (CIs) of q^ could be calculated based on the t distribution for the synthetic data.

## CI overlap

CI overlap measures the overlap of the CIs derived from the original data and the synthetic data (27,28). The overlap (or lack thereof) of CIs does not imply or test statistical significance. Instead, the higher the overlap, the better the data utility. Let U_ori_ and L_ori_ be the upper and lower bounds of the confidence interval for an estimate derived from the original data, U_syn_ and L_syn_ be the upper and lower bounds of the CI for the same estimate derived from the synthetic data, and U_over_ and L_over_ denote the upper and lower bounds of the overlap of the CIs derived from the original and synthetic data sets for the estimate. The CI overlap is

CI ​ overlap ​ = ( (U_o v e r_ − L_o v e r_)/(U_o r i_ − L_o r i_) + (U_o v e r_ − L_o v e r_)/(U_s y n_ − L_s y n_) ) / 2 Actual text: CI overlap equals sum of two quantities divided by 2. The first quantity is the difference of U subscript over and L subscript over divided by the difference of U subscript ori and L subscript ori, the second quantity is the difference of U subscript over and L subscript over divided by the difference of U subscript syn and L subscript syn.

When there is no overlap, CI overlap = 0.

## Propensity score measurement

Propensity score measurement is a method used to distinguish the synthetic from the original data (28,29). The main steps of deriving the propensity measurements are: 1) stack the original data and the synthetic data and for each record include an indicator for the data source; 2) for each record in the stacked data set, calculate the propensity of being in the original data from a logistic regression model that includes the synthesized variables as predictors; 3) compare distributions of the estimated propensity scores. Assuming the original and synthetic data have the same number of records, if the two data have similar distributions, the chance for any chosen record to belong to the original or the synthetic data would be similar (around 50%), and the estimated propensity scores would be close to 0.5 for all records. On the other hand, if the two data sets are completely distinguishable, the estimated propensity score for each record would move away from 0.5. For example, the estimated propensity scores for records from one data set tend to be close to 1, and the estimated propensity scores for records from the other data set tend to be close to zero.

Because the survey design information was synthesized in this study (Approaches 1 and 2), the survey design variables and sampling weights were used to estimate the propensity scores from a weighted logistic regression model using the SAS surveylogistic procedure (25), and the variables synthesized (Table 1) were included as predictors. Because multiple synthetic data sets were created, the first copy of the synthetic data set was used for this analysis.

## Analysis of sampling weights from Approach 2

For Approach 2, using the parametric method, both the R synthpop package and the IVEware synthesized the sampling weights from a linear regression model; however, the square root transformation of the sampling weights was used for the R synthpop package, while the IVEware SYNTHESIZE module used the bounds function for the sampling weights. For the nonparametric method (CART), the sampling weights were synthesized using random draws of the observed values from the homogeneous clusters created from the CART model. The synthesized sampling weights from different modeling options may lead to differences between the synthesized data. Thus, quantiles and means of synthetic sampling weights were compared with the original sampling weights. Departure from the original sampling weights suggests low data utility.

## Disclosure risk analysis via average matching probability

The synthetic data approach applied to complex survey data can protect an individual’s confidentiality while preserving data utility. The previously described analyses for this report focused on data utility. This analysis focused on disclosure risk using the average matching probability (30–32). Synthetic data are generated based on statistical models. When the synthetic data set is very similar to the original data set (for example, the synthetic data set contains records with identical or almost identical values as records in the original data), the chance of disclosure is greater. Suppose an intruder knew specific information about a target person who participated in a survey. These variables could be linked to the synthetic data sets to potentially identify the target individual. Let P_match be the average matching probability, which can be derived as

P_match = (∑_i = 1_^m^ n_i_ / N m a t c h_i_)/(m) Actual text: P underscore match equals sum of the quantity n subscript i over Nmatch subscript i, from i equals 1 to m, divided by m.

where n_i_ is the number of correct matches for synthetic data i (a correct match means the match is a true match [all variables of a matched case are the target person's real values]). For high-dimensional data, n_i_ would most likely be 0 (not a match) or 1 (a true match). The chance of n_i_ being greater than 1 is small as the likelihood of two records in synthetic data with identical measurements across all variables is expected to be small. However, in this study, a subset of the survey variables was used for data synthesis, so having common measurements across all 12 variables is possible; consequently, n_i_ could be greater than 1. Nmatch_i_ is the number of records fulfilling the matching criteria in the synthetic data i (the total number of records in the synthetic data i with identical information the intruder possessed); m is the total number of synthetic data sets.

For example, suppose the intruder knows the target person is a 50-year-old White female with a Ph.D. Checking the synthetic data, if the intruder finds two White 50-year-old women with a Ph.D., then Nmatch_i_ = 2. Suppose neither of the two subjects is the target person (that is, the remaining variables are not the real values of the target person); then it is a false match and n_i_ = 0, and the intruder would have a 0% chance of identifying the target person. If one of the two subjects is the target person (that is, the remaining variables for this record are the same as those of the target person), then it is a true match and n_i_ = 1, and the intruder would have a 50% chance of identifying the target person. If all of these two matched records have identical measurements for all 12 variables like the target person, then n_i_ = 2, and the intruder would have a 100% chance of identifying the target person. The overall matching probability can be derived after calculating n_i _and Nmatch_i_ for all synthetic data sets.