# Introduction

Federal agencies, such as the National Center for Health Statistics (NCHS), collect, analyze, and disseminate information for statistical purposes. They conduct national surveys and release microdata (data containing information about individuals) for public use. To protect survey participants’ confidentiality, statistical disclosure limitation (SDL) techniques have been used to de-identify data (1–4). Some commonly used SDL methods include deletion of data, data coarsening, top (or bottom) coding, adding noise to data, data swapping, and using synthetic data (5–11).

Deleting records of individuals vulnerable to disclosure protects their confidentiality; however, information about these individuals is lost. For example, individuals with very high income or uncommon characteristics, such as rare diseases, are removed from the public-use data. As a result, the released data may lead to biased estimates of specific characteristics of the study population. Data coarsening creates coarsened categories on variables with sensitive information such that detailed information is not released. For example, income categories are released for public use instead of exact income to protect sensitive income information. This prevents disclosure but also precludes detailed statistical analysis on these variables. Top (or bottom) coding truncates data at certain cut-off values; for example, the age of a person 85 years or older is reported as 85 years old. Adding noise to the data adds a random number to the original data values, so the data are not as accurate as the original data (5,12). However, this increases variance estimates, which may lead to an increased type II error. Data swapping methods exchange data values for pairs of individuals (6,13). As a result, the original data values are released for public use. However, because data values are switched between individuals, the marginal distribution of the swapped variable(s) (such as survey data with sampling weights associated with different subjects) and conditional inferences of the swapped variable(s) with respect to other variables may change.

Use of synthetic data may offer another option. Partially synthetic data are generated by replacing some of the observed values, whereas fully synthetic data are derived by replacing all of the observed values with sampled values from the approximate probability distributions of variables estimated from the original data (1,2,7,8,11). The goal of synthetic data is to preserve essential statistical features and variable relationships of the original data such that statistical inference based on the synthetic data is close to that of the original data. In certain circumstances, this method may be preferable for protection because only some or none of the original data are released. However, sophisticated statistical methods are required to model the joint distribution of all variables. Departure from the original distributions may lead to misleading results. Moreover, it could produce records with identical or almost identical values as records in the original data if the model to create synthetic data is saturated; that is, the model fits the data perfectly and consequently yields predictions very close to the truth. As a result, synthetic data are not guaranteed to be risk-free.

The SDL techniques mentioned above can be used alone or together. Combining SDL techniques may lead to better data utility and better protection (14). In practice, a trade-off always exists between data utility (the validity of inference using synthetic data) and data confidentiality (4,15). A good SDL technique retains data utility and, in the meantime, protects confidentiality. Yet ill-intentioned intruders may still identify an individual’s identity and violate participants’ privacy. Usually, individuals with a unique combination of certain observable traits are vulnerable to identification. In recent years, the synthetic data approach has been gaining popularity in many fields as an approach to retaining data utility and protecting confidentiality. However, creating synthetic data for complex surveys remains challenging due to the complex survey design features, the high dimensionality of the survey data with different distributional forms, and unique data structures such as skip patterns and missing data.

This report studies the impact of incorporating survey design information (strata and primary sampling units [PSUs], referred to in this report as design variables; and sampling weights) when synthesizing sample survey data using parametric and nonparametric methods. The Research and Development Survey (RANDS) (https://www.cdc.gov/nchs/rands/) (16–18) was used to create synthetic data. RANDS is a series of surveys conducted by NCHS that was designed to explore the use of recruited web panels to collect information on national health outcomes and to supplement NCHS’s question-response evaluation and statistical research. Nine rounds of cross-sectional surveys (RANDS 1 to RANDS 9) and three rounds of RANDS During COVID-19 surveys were completed by the spring of 2024. RANDS During COVID-19 surveys, a special iteration of RANDS, collected timely information on COVID-19-related health outcomes from U.S. adults (19). COVID-19 Survey Round 3, conducted in the summer of 2021 and the most recent RANDS at the time of the study, was used for this report.