# Conclusion

Measurement of progress toward target attainment and elimination of health disparities in Healthy People has evolved since its inception in 1979, and this report outlines the latest developments that expand and build on the work of previous decades and further addresses methodological issues and limitations previously identified. Changes for Healthy People 2030 have been implemented to:

- Enhance understanding of progress toward target attainment and elimination of health disparities by considering multiple measures (also referred to as a multipronged approach in Healthy People 2020).
- Expand the scope of disparities measures to provide a more complete picture of disparities than was previously considered.
- Improve variance estimation for disparities measures using the resampling/bootstrap procedure described in the Appendix: Measures of Variability.
- Beyond the health disparities data available on the Healthy People website, provide users with an Excel-based tool (the Health Disparities Tracking Tool) to calculate disparities from their own input data, calculate SEs and 95% CIs (when applicable), assess changes in disparities over time, and generate dot plots (equiplots) (25) and trend charts to track disparities.

In doing so, the measurement approaches outlined in this report not only build on the work of past decades, but also further advance the potential utility of Healthy People 2030 for the broader public health community.