# Discussion

## Progress

Assessments of progress, whether using the percentage of targeted change achieved for objectives moving toward their targets or the percentage change from baseline for other scenarios (including objectives moving away from their baselines and targets as well as assessments of progress by population subgroups), are subject to a few considerations. In Healthy People 2020 reports, the percentage change from baseline for the total population was only calculated and presented for objectives that were moving away from their baselines and targets (2–4). Plans for Healthy People 2030 reports are yet to be determined. However, consistent with Healthy People 2020, the percentage change from baseline will not factor into the determination of the Healthy People 2030 progress status categories for objectives that are moving in the desired direction, toward their targets; see the “Determination of Healthy People 2030 status categories” section and Table B. While the percentage of targeted change achieved is the primary measure for objectives moving in the desired direction, analyses based on the percentage change from baseline allow for complementary data-driven assessments that can inform policy discussions, for example, regarding progress away from the targets or progress by population subgroups.

Also, assessments of progress in Healthy People 2030 do not consider trend data or intermediate data points. There may be situations, for example, when the target is met for a particular objective at an intermediate timepoint but not at the most recent timepoint. And trend analyses, such as analyses using the National Cancer Institute’s Joinpoint software (22,23) are not currently conducted across the initiative in assessments of progress. Note that Healthy People 2030 only required assurance of three data points over the course of the decade, which limits the types of analyses that can be conducted related to progress.

Another important consideration is that the Healthy People 2030 measures for assessing progress, the percentage of targeted change achieved, and percentage change from the baseline have different denominators, as the former uses the targeted change at baseline (difference between the target and baseline values) and the latter uses only the baseline value. As a result, a 10% change from baseline (in the direction of the target), for example, is not equivalent to a 10% of targeted change achieved.

## Health Disparities

To recap, the six disparities measures used in Healthy People 2030, as summarized in Table C, are the between-group rate difference and ratio, allowing comparisons of each population subgroup to the reference rate; the maximal rate difference and ratio, which are overall measures that allow comparisons between the highest and lowest group rates for a given population characteristic; and the summary rate difference and ratio, which are overall measures that compare the reference group rate to the average rate of all other subgroups.

Using appropriate measures of disparity has recently been identified as a key principle for health equity (24). In the absence of a single gold standard measure, the three primary characteristics discussed in this report for selecting the suite of six health disparities measures for Healthy People 2030, namely, absolute versus relative, between-group versus overall, and maximal versus summary, each have pros and cons that may be considered in the selection of specific measures. Absolute measures are easier to visualize than relative measures on a linear scale, which most people are accustomed to using. However, because relative measures are unit-free, they can be used to compare objectives with different units of measure (rate per 100,000, rate per 10,000, percent, etc.). Between-group measures are useful, particularly in analyses that focus on a specific population, such as the Hispanic or Latino population, because the group of interest can be kept the same in comparisons. On the other hand, overall measures are useful for analyses of data across multiple population group rates, such as analyses across groups by educational attainment. Finally, maximal measures may be attractive for their simplicity of calculation, which only requires the two extreme group rates; however, they are also more sensitive to changes in the values used in their calculations, which are the highest and lowest group rates for a given population characteristic. Conversely, summary measures consider all the population subgroup rates for a given population characteristic, and they are less subject to variability over time, particularly for population characteristics with a larger number of groups, such as race and ethnicity, but they are more complex to calculate and understand.

Again, assessing changes in disparities over time is primarily done on a relative scale to allow for direct comparisons between multiple health disparities measures. However, analyses of changes over time could be done on an absolute scale when only considering a single measure, such as the SRR in the Healthy People 2020 Final Review (2).

Differences Between Healthy People 2020 and 2030

- Healthy People 2030 adds two measures (summary rate difference and between-group rate difference) to the suite of four disparities measures used in Healthy People 2020. This expanded suite of six measures includes absolute and relative, between-group and overall, and summary and maximal measures, ensuring congruence and complementarity in the scale and scope of measures used.
- Healthy People 2030 expands the use of the “percentage change from the baseline” to all core objectives (and population subgroups), which provides advantages compared with relying primarily on the “percentage of targeted change achieved.” Analyses based on the percentage change from baseline allow for the classification of objectives into data-driven categories that may inform policy discussions beyond what the percentage of targeted change achieved provides.
- Healthy People 2030 reintroduces the resampling/bootstrap procedure to estimate measures of variability (SEs and 95% CIs) for all six disparities measures. In Healthy People 2010, measures of variability for the Index of Disparity, a special case of the SRR, were based on the resampling/bootstrap procedure. Measures of variability for the between-group rate ratio in Healthy People 2010 and the four disparities measures in 2020 were based on analytic, formula-based approximations to their SEs. The resampling/bootstrap procedure for Healthy People 2030 accounts for the uncertainty in the ranking of the groups, the variability in the reference group rate, and the correlations among the ordered group rates, which are not accounted for in the formula-based approach.