# Findings

This section presents examples of the Healthy People 2030 measures of progress and disparities defined in this report, along with how these data may be analyzed and displayed in publications and/or online tools.

## Findings Related to Progress Toward Target Attainment

Table D presents examples of how progress data may be displayed for selected Healthy People 2030 objectives as of May 2024. The table displays the progress status category; the baseline, most recent, and target values; the percentage change from baseline for all objectives; the percentage of targeted change achieved for objectives that were moving toward their targets; and the statistical significance of the movement. For objectives that were moving toward or that had met or exceeded their targets at the most recent data point, the statistical significance of the movement was that of the percentage of targeted change achieved. For objectives that were moving away from their baselines and targets, the statistical significance of the movement was that of the percentage change from baseline.

Table D

Examples of progress status calculations and categories for Healthy People 2030

Objective | Progress status category | Baseline value (year) | Most recent value (year) | Target | Percent change from baseline | Percent of targeted change achieved^1^ | Movement statistically significant^2^
Reduce stroke deaths — HDS‑03Stroke deaths (per 100,000 population, age adjusted) | Getting worse | 37.1 (2018) | 39.5 (2022) | 33.4 | 6.5 | Not applicable | Yes
Increase the proportion of adults with diabetes who have a yearly eye exam — D‑04Annual eye examinations among adults with diagnosed diabetes (percent, age adjusted) | Little or no detectable change | 64.8 (2019) | 64.6 (2022) | 70.3 | -0.3 | Not applicable | No
Reduce emergency department visits related to nonmedical use of prescription opioids — MPS‑02Emergency department visits for harms from nonmedical use of prescription opioids (per 10,000 population) | Target met or exceeded | 3.9 (2016–2017) | 2.9 (2020–2021) | 3.5 | -25.6 | 250.0 | No
Reduce new cases of work-related hearing loss — OSH‑06New cases of occupational hearing loss (per 10,000 full-time workers) | Target met or exceeded | 1.7 (2016) | 1.4 (2019) | 1.4 | -17.6 | 100.0 | Not tested
Reduce the syphilis rate in men who have sex with men — STI‑05New cases of primary and secondary syphilis among men who have sex with men (per 100,000 men) | Improving | 419.0 (2018) | 402.0 (2020) | 392.0 | -4.06 | 63.0 | Not tested

1 Calculated for all objectives except in the following two scenarios: a) the objective is moving away from the baseline and target values or b) the baseline and target values for the objective are equal because the targeted change from baseline was zero. Objectives in either of these two scenarios for which percentage of targeted change achieved is not calculated are indicated as “Not applicable” in the table.

2 Assessed at the 0.05 level using a one-sided test when measures of variability are available. Statistical significance is based on the percentage change from baseline for objectives moving away from their baseline and target values, or when the baseline and target values for the objective are equal. For all other objectives, statistical significance is based on the percentage of targeted change achieved. Objectives with data for which measures of variability were unavailable are indicated as “Not tested” in the statistical significance column.

SOURCE: National Center for Health Statistics, Healthy People 2030 database.

The examples in Table D illustrate several scenarios.

- Reduce stroke deaths (HDS-03)—The 2022 data point moved away from the baseline and target values, with a percentage change of 6.5% from the baseline rate of 37.1 per 100,000 (age adjusted). Because the percentage change from baseline was statistically significant, the objective was designated as GETTING WORSE.
- Increase the proportion of adults with diabetes who have a yearly eye exam (D-04)—The 2022 data point moved away from the baseline and target values, with a percentage change of –0.3% from the baseline of 64.8% (age adjusted). Because the percentage change from baseline was not statistically significant, the objective was designated as demonstrating LITTLE OR NO DETECTABLE CHANGE.
- Reduce emergency department visits related to nonmedical use of prescription opioids (MPS-02)—The 2020–2021 data point exceeded the target of 3.5 per 10,000 population, with a percentage of targeted change achieved of 250.0%. Although the percentage of targeted change achieved was not statistically significant, the objective was designated as TARGET MET OR EXCEEDED (Table B).
- Reduce new cases of work-related hearing loss (OSH-06)—The 2019 data point met the target of 1.4 per 10,000 full-time workers, with a percentage of targeted change achieved of 100.0%. Although statistical significance could not be assessed (measures of variability unavailable), the objective was designated as TARGET MET OR EXCEEDED.
- Reduce the syphilis rate in men who have sex with men (STI-05)—The objective was moving toward its target at the 2020 data point but had not met or exceeded the target of 392.0 per 100,000 men. The percentage of targeted change achieved was 63.0% and statistical significance could not be tested due to lack of measures of variability. As a result, the objective was designated as IMPROVING.

## Findings Related to Progress by Population Subgroups

The Table shows age-adjusted suicide rates—Healthy People 2030 objective Mental Health and Mental Disorders (MHMD)-01, a Leading Health Indicator—for the period 2018–2022 by the following race and ethnicity groups: Hispanic or Latino (subsequently, Hispanic); American Indian or Alaska Native, not Hispanic or Latino (American Indian or Alaska Native); Asian, not Hispanic or Latino (Asian); Native Hawaiian or Other Pacific Islander, not Hispanic or Latino (Native Hawaiian or Other Pacific Islander); Black or African American, not Hispanic or Latino (Black); White, not Hispanic or Latino (White); and two or more races, not Hispanic or Latino (multiracial).

All but the American Indian or Alaska Native and the White populations had already met or exceeded the Healthy People 2030 target of 12.8 suicides per 100,000 (age adjusted) at the 2018 baseline (Table). As a result, the assessment of progress toward target attainment by population subgroup does not meaningfully convey differences in how the group-specific suicide rates changed from 2018 to 2022. Instead, the percentage change from baseline in suicide rates provides a more complete comparative assessment.

Table

Age-adjusted suicide rate for selected race and ethnicity groups, 2018–2022

Race and ethnicity | 2018 (baseline) | | 2019 | | 2020 | | 2021 | | 2022 | | Percentage change from 2018 to 2022
| Rate per 100,000 | Standard error | Rate per 100,000 | Standard error | Rate per 100,000 | Standard error | Rate per 100,000 | Standard error | Rate per 100,000 | Standard error | Percent | Standard error^1^ | 95% confidence interval^2^
| Rate per 100,000 | Standard error | Rate per 100,000 | Standard error | Rate per 100,000 | Standard error | Rate per 100,000 | Standard error | Rate per 100,000 | Standard error | Percent | Standard error^1^ | Lower limit | Upper limit
Hispanic or Latino | 7.4 | 0.116 | 7.3 | 0.113 | 7.5 | 0.114 | 7.9 | 0.115 | 8.1 | 0.116 | 8.9 | 2.212 | 4.5 | 13.5
American Indian or Alaska Native, not Hispanic or Latino | 22.3 | 0.970 | 22.5 | 0.976 | 23.9 | 1.002 | 28.1 | 1.085 | 27.1 | 1.078 | 21.7 | 6.581 | 8.4 | 36.6
Asian, not Hispanic or Latino | 6.7 | 0.187 | 6.7 | 0.185 | 6.4 | 0.180 | 6.8 | 0.185 | 6.9 | 0.181 | 2.1 | 3.879 | -5.3 | 10.0
Native Hawaiian or Other Pacific Islander, not Hispanic or Latino | 11.9 | 1.409 | 14.4 | 1.536 | 12.5 | 1.420 | 12.6 | 1.401 | 14.3 | 1.473 | 20.3 | 17.343 | -11.6 | 63.7
Black or African American, not Hispanic or Latino | 7.3 | 0.134 | 7.5 | 0.136 | 7.8 | 0.138 | 8.7 | 0.146 | 8.9 | 0.146 | 23.3 | 2.770 | 17.4 | 29.4
White, not Hispanic or Latino | 18.1 | 0.097 | 17.7 | 0.096 | 16.9 | 0.094 | 17.4 | 0.096 | 17.6 | 0.096 | -2.9 | 0.752 | -4.3 | -1.4
Two or more races, not Hispanic or Latino | 9.0 | 0.429 | 8.8 | 0.417 | 9.6 | 0.424 | 9.7 | 0.421 | 10.5 | 0.435 | 17.1 | 6.873 | 3.5 | 32.6

1 Calculated using formula 1 in the Appendix: Measures of Variability.

2 Calculated using an asymmetric lognormal confidence interval for the ratio, 100 • exp [ln (m_t_ / m_0_) ± 1.959964 • S E_ln (m_t_ / m_0_)_] − 1 , where the standard error of the logarithm of the ratio is calculated using formula 3 in the Appendix: Measures of Variability.

NOTES: People of Hispanic origin may be of any race. Mortality rates are based on single-race estimates by selected race (American Indian or Alaska Native, Asian, Black or African American, Native Hawaiian or Other Pacific Islander, White, two or more races) and ethnicity (Hispanic or Latino, not Hispanic or Latino) population groups with underlying cause of death ICD–10 codes *U03, X60–X84, and Y87.0, and are age adjusted to the year 2000 standard population.

SOURCES: National Center for Health Statistics, National Vital Statistics System, mortality (NVSS–M) and Census, population estimates.

The White population, historically with higher age-adjusted suicide rates than all but the American Indian or Alaska Native population, showed a percentage decrease of 2.9% (95% CI: 1.4%–4.3%) between 2018 and 2022, from 18.1 to 17.6 suicides per 100,000 (age adjusted) (Table). However, the Hispanic population, as well as the American Indian or Alaska Native, Black, and multiracial populations, showed statistically significant increases between 2018 and 2022, ranging from 8.9% (95% CI: 4.5%–13.5%) for the Hispanic population to 23.3% (95% CI: 17.4%–29.4%) for the Black population. The percentage changes between 2018 and 2022 for the remaining race and ethnicity groups were not statistically significant at the 0.05 level.

## Findings Related to Disparities and Changes in Disparities Over Time

Figures 1–3 provide examples of the Healthy People 2030 disparities measures defined in this report, along with how these data may be analyzed and displayed in publications and/or online tools. Figures 1–3 show disparities in the age-adjusted suicide rates by race and ethnicity, using the data in the Table. The lowest suicide rate (reference) among the selected race and ethnicity groups was seen in the Asian population throughout 2018–2022. The top panel in Figure 1 visualizes the change over time in the gap between the reference rate and the suicide rate for the White population. The between-group disparity in suicide rates can be measured using an absolute measure, the rate difference RD_g _(bottom right panel in Figure 1), which decreased by 5.8% from 11.4 in 2018 to 10.7 in 2022, or a relative measure, the rate ratio RR_g_ (bottom left panel in Figure 1), which decreased by 4.8% from 2.696 in 2018 to 2.566 in 2022 but was not statistically significant at the 0.05 level. As a result, the two between-group disparities measures lead to different classifications for the change in disparity for the White population over the 2018–2022 tracking period, with the rate difference RD_g _indicating a narrowing and the rate ratio RR_g_ indicating little or no detectable change (Table C).

Figure 1

Example output from the Health Disparities Tracking Tool showing between-group disparities in age-adjusted suicide rate, by race and ethnicity: 2018–2022

Figure 1 is an example output from the Health Disparities Tracking Tool showing between-group disparities in the age-adjusted suicide rate by race and ethnicity for the time period 2018 through 2022. The top panel shows the change over time in the gap between the reference rate and the suicide rate for the White non-Hispanic population. The between-group disparity in suicide rates can be measured using an absolute measure, the between-group rate difference (bottom right panel), or a relative measure, the between group rate ratio (bottom left panel).

Figure 2 (top panel) visualizes the change over time in the gap between the highest and lowest suicide rates among the selected race and ethnicity groups. The maximal overall disparity in suicide rates can be measured using an absolute measure, the maximal rate difference MRD (Figure 2, bottom right), which increased by 30.2% from 15.5 in 2018 to 20.2 in 2022, or a relative measure, the maximal rate ratio MRR (Figure 2, bottom left), which increased by 19.2% from 3.315 in 2018 to 3.953 in 2022, leading to a widening of disparities for both measures.

Figure 2

Example output from the Health Disparities Tracking Tool showing maximal disparities in age-adjusted suicide rate, by race and ethnicity: 2018–2022

Figure 2 is an example output from the Health Disparities Tracking Tool showing maximal disparities in the age-adjusted suicide rate by race and ethnicity for the time period 2018 through 2022. The top panel shows the change over time in the gap between the highest and lowest suicide rates by race and ethnicity. The maximal disparity in suicide rates can be measured using an absolute measure, the maximal rate difference (bottom right panel), or a relative measure, the maximal rate ratio (bottom left panel).

Figure 3 (top) visualizes the change over time in the gap between the reference rate and the average suicide rate among the groups other than the group that achieved the reference rate. The summary overall disparity in suicide rates can be measured using an absolute measure, the summary rate difference SRD (Figure 3, bottom right), which increased by 27.5% from 5.9 in 2018 to 7.6 in 2022, or a relative measure, the summary rate ratio SRR (Figure 3, bottom left), which increased by 11.7% from 1.883 in 2018 to 2.103 in 2022, leading to a widening of disparities for both measures.

Figure 3

Example output from the Health Disparities Tracking Tool showing summary disparities in age-adjusted suicide rate, by race and ethnicity: 2018–2022

Figure 3 is an example output from the Health Disparities Tracking Tool showing summary disparities in the age-adjusted suicide rate by race and ethnicity for the time period 2018 through 2022. The top panel shows the change over time in the gap between the reference rate and the average suicide rate among racial and ethnic populations other than the group that achieved the reference rate. The summary disparity in suicide rates can be measured using an absolute measure, the summary rate difference (bottom right panel), or a relative measure, the summary rate ratio (bottom left panel).

An Excel-based tool (the Health Disparities Tracking Tool) allowing users to replicate the charts shown in Figures 1–3 and calculate all disparities measures, changes in disparities over time, and bootstrapped SEs and 95% CIs, is available for download from: https://www.cdc.gov/nchs/healthy_people/hp2030/hp2030-methods.htm.