# Methods

Healthy People 2030 objectives are tracked using a variety of measurement units, such as percentages, rates, and counts. Of the current 359 Healthy People 2030 core objectives, 239 (66.6%) are measured using percentages and 85 (23.7%) are measured using rates (for example, per 100,000 population), for a total of 324 objectives (90.3%) measured using either a percentage or a rate. The remaining 35 objectives (9.7%) use other measurement units, including but not limited to case or event counts and volumetric units. For this report, the term “rate” is used as shorthand for rate, percentage, proportion, or any other unit of measurement for which a meaningful assessment of disparities can be made. Disparities are not usually assessed for objectives that are measured using counts, because any differences between population groups for such objectives may not be distinguishable from differences in the relative sizes of the groups in the population (10).

## Measuring Progress

Analyses of progress in Healthy People are multifaceted. Assessment of progress toward Healthy People 2030 targets focus on the total targeted population—because that is the basis for target setting for each objective—and uses the “percentage of targeted change achieved” for objectives moving toward their targets. The “percentage change from baseline” can also be calculated for all measurable objectives with a baseline and at least one follow-up data point, regardless of their targets or whether the change is in the desired direction.

### Measuring progress toward target attainment

At the launch of Healthy People 2030 in August 2020, targets were set to be achieved by the end of the decade. Progress toward target attainment may be evaluated for Healthy People 2030 objectives that have a baseline, a target and desired direction of change, and at least one follow-up data point, and is monitored throughout the decade. Progress toward target attainment cannot be evaluated for objectives with only baseline data and objectives with no Healthy People 2030 targets or desired direction of change (developmental and research objectives). As explained below, objectives for which progress toward target attainment can be measured fall under three mutually exclusive categories: moving toward their targets; moving away from their targets; or demonstrating little or no detectable change.

#### Progress for objectives moving toward their targets

As in Healthy People 2020, the percentage of targeted change achieved quantifies progress toward target attainment for Healthy People 2030 objectives that are moving toward their targets. The percentage of targeted change achieved expresses the difference between the baseline and the most recent value relative to the targeted change from baseline (4), as follows: Percentage of targeted change achieved = (Most recent value − Baseline value)/(HP2030 target − Baseline value) · 100

The assessment of statistical significance of the percentage of targeted change achieved (when measures of variability are available) is detailed in the Appendix: Measures of Variability.

#### Progress for objectives moving away from their targets

The percentage of targeted change achieved does not adequately quantify progress for objectives moving away from their targets, as demonstrated in the Technical Appendix of the Healthy People 2010 Final Review (11). To quantify progress toward target attainment for Healthy People 2030 objectives that are moving away from their baseline and target values, the percentage change from baseline, discussed in the next section, is used instead to capture the deficit from baseline and faithfully represent the progress needed to achieve the target. For example, a percentage change from baseline of 10% in magnitude (absolute value)—and away from the target—indicates that the objective is 10% in deficit relative to its baseline, a deficit that would need to be made up in addition to the targeted change from baseline once the baseline value is regained.

#### Progress for objectives demonstrating little or no detectable change

Healthy People 2030 objectives that are moving toward their targets but for which the percentage of targeted change achieved is small or, otherwise, not statistically significant (when measures of variability are available) are categorized as having demonstrated little or no detectable change. Objectives that are moving away from their targets but for which the percentage change from baseline is small or not statistically significant, as well as for objectives for which the change from baseline is zero, are similarly categorized. When measures of variability are not available, the specific numerical threshold for the magnitude of the percentage of targeted change achieved or the percentage change from baseline to be considered little or not detectable is discussed in the “Determination of Healthy People 2030 status categories” section.

### Percentage change from baseline for all objectives

The percentage change from baseline is defined as: Percentage change from baseline = (Most recent value − Baseline value)/(Baseline value) · 100

Note that the percentage change from baseline can also be expressed as a function of the ratio between the most recent and baseline values:

Percentage change from baseline = [(Most recent value)/(Baseline value) − 1] · 100

The assessment of the statistical significance of the percentage change from baseline (when measures of variability are available) is detailed in the Appendix: Measures of Variability.

The percentage change from baseline could be calculated and presented for any objective that has a baseline and at least one follow-up data point, regardless of its target or desired direction of change.

The percentage change from baseline quantifies change over time in the indicator that is tracked by a given Healthy People 2030 objective (for example, Healthy People 2030 objective AHS-01, “Increase the proportion of people with health insurance,” tracks the percentage of people under 65 who report coverage by any type of public or private health insurance). As a relative measure, the percentage change from baseline is unit-free and, therefore, allows for comparisons for the total population among objectives across the Healthy People 2030 topics (health conditions, health behaviors, populations, settings and systems, and social determinants of health); among population subgroups for which data are available; and, when applicable, across disparities measures when tracking changes in disparities over time.

Analyses based on the percentage change from baseline allow for the classification of Healthy People 2030 objectives into data-driven categories.

- Objectives for which the rate for the total population is moving away from its baseline and target values may be categorized as GETTING WORSE or demonstrating LITTLE OR NO DETECTABLE CHANGE depending on the statistical significance of the percentage change from baseline (when applicable) and whether the change is 10% or more in absolute value (Table B).
- As a supplement to the measurement of progress toward target attainment, described in “Measuring Progress Toward Target Attainment,” objectives that are moving in the desired direction may be further categorized; for example, as showing less than 10%, 10%–49%, 50%–99%, or at least 100% change from baseline, akin to the categorization of changes in disparities in Healthy People 2010 (12). Objectives that are moving away from their baselines may be similarly characterized. Such analyses would inform a more in-depth comparative assessment of progress and may be appropriate for: (a) all Healthy People 2030 objectives; (b) a selected subset of Healthy People 2030 objectives, such as the Healthy People 2030 Leading Health Indicators; or (c) population subgroups.

Table B

Classification of Healthy People 2030 objectives, by progress status

Objective status | Short explanation
TARGET MET OR EXCEEDED | Target met or exceeded.
IMPROVING | Movement is toward the target and is either:
IMPROVING | – Statistically significant when measures of variability are available.
IMPROVING | OR – Ten percent or more of the targeted change when measures of variability are unavailable.
LITTLE OR NO DETECTABLE CHANGE | Objective demonstrates little or no detectable change, because either:
LITTLE OR NO DETECTABLE CHANGE | – Movement toward the target is not statistically significant when measures of variability are available.
LITTLE OR NO DETECTABLE CHANGE | OR – Movement is toward the target, but the objective has achieved less than 10% of the targeted change when measures of variability are unavailable.
LITTLE OR NO DETECTABLE CHANGE | OR – Movement is away from the baseline and target and is not statistically significant when measures of variability are available.
LITTLE OR NO DETECTABLE CHANGE | OR – Movement is away from the baseline and target, but the objective has moved less than 10% relative to its baseline when measures of variability are unavailable.
LITTLE OR NO DETECTABLE CHANGE | OR – There was no change between the baseline and most recent data point.
GETTING WORSE | Movement is away from the baseline and target and is either:
GETTING WORSE | – Statistically significant when measures of variability are available.
GETTING WORSE | OR – Ten percent or more relative to the baseline when measures of variability are unavailable.
BASELINE ONLY | Objective has only baseline data; progress cannot be assessed.
DEVELOPMENTAL | Objective is a high-priority public health issue associated with (an) evidence-based intervention(s), but it doesn’t yet have reliable baseline data.
RESEARCH | Objective represents a public health issue with a high health or economic burden or significant disparities between population groups, but it is not yet associated with (an) evidence-based intervention(s).

SOURCE: National Center for Health Statistics, Healthy People 2030 database.

### Determination of Healthy People 2030 status categories

Healthy People 2030 objectives can be classified into several mutually exclusive categories: TARGET MET OR EXCEEDED, IMPROVING, LITTLE OR NO DETECTABLE CHANGE, GETTING WORSE, BASELINE ONLY, DEVELOPMENTAL, or RESEARCH. Progress cannot be assessed for the last three categories of objectives, because those objectives have only baseline data, do not have reliable baseline data, or are not yet associated with (an) evidence-based intervention(s), respectively. As was the case in Healthy People 2020, the first four categories are the progress status categories used for Healthy People 2030 core objectives with tracking data (a baseline and at least one follow-up data point).

#### Objectives that met or exceeded their targets

When the desired direction is an increase, an objective is considered to have met or exceeded the target at the most recent timepoint if its most recent value is at or above the Healthy People 2030 target. On the other hand, when the desired direction is a decrease, an objective has met or exceeded its target if the most recent value is at or below the Healthy People 2030 target.

Consistent with Healthy People 2020, Healthy People 2030 objectives that have met or exceeded their target are classified in the TARGET MET OR EXCEEDED progress status category (Table B). In this scenario, the percentage of targeted change achieved is 100% or more. Even though the statistical significance of the percentage of targeted change achieved is calculated and displayed in published tables, objectives that have met or exceeded their target are categorized as TARGET MET OR EXCEEDED regardless of whether the percentage of targeted change achieved was statistically significant.

#### Objectives moving toward their targets

When the desired direction is an increase, an objective is moving toward the target at the most recent timepoint if its most recent value is higher than the baseline but remains lower than the Healthy People 2030 target. On the other hand, when the desired direction is a decrease, an objective is moving toward the target if the most recent value is lower than the baseline but remains higher than the Healthy People 2030 target.

Consistent with Healthy People 2020, Healthy People 2030 objectives that are moving toward but have not met or exceeded their targets are classified in the IMPROVING or LITTLE OR NO DETECTABLE CHANGE progress status categories, depending on the magnitude or, when applicable, statistical significance of the percentage of targeted change achieved (Table B). Specifically, an objective that is moving toward but has not met or exceeded its target at the most recent timepoint is classified as IMPROVING if the percentage of targeted change achieved is statistically significant (when standard errors [SEs] are available), regardless of the magnitude of the change, or, when statistical significance cannot be tested, if 10% or more of the targeted change is achieved. If, when tested for statistical significance, the percentage of targeted change achieved is not statistically significant, or, when statistical significance cannot be tested, if less than 10% of the targeted change is achieved, the objective is classified as showing LITTLE OR NO DETECTABLE CHANGE.

#### Objectives moving away from their baselines and targets

When the desired direction is an increase, an objective is moving away from the baseline and target at the most recent timepoint if its most recent value is lower than the baseline and Healthy People 2030 target. On the other hand, when the desired direction is a decrease, an objective is moving away from the baseline and target if the most recent value is higher than its baseline and target.

Consistent with Healthy People 2020, Healthy People 2030 objectives that are moving away from the baselines and targets are classified in the GETTING WORSE or LITTLE OR NO DETECTABLE CHANGE progress status categories (Table B). Specifically, an objective that is moving away from its baseline and target at the most recent timepoint is classified as GETTING WORSE if the percentage change from baseline is statistically significant (when SEs are available), regardless of the magnitude of the change, or, when statistical significance cannot be tested, if the change from baseline is 10% or more in magnitude (absolute value). An objective is classified as showing LITTLE OR NO DETECTABLE CHANGE when the percentage change from baseline is not statistically significant (when SEs are available), or, in the absence of significance testing, if the absolute change from baseline is less than 10% in magnitude.

#### Objectives that show no change between the baseline and most recent data points

When the most recent value for an objective is equal to the baseline value, there is no movement in either direction. In this scenario, either the percentage change from baseline or the percentage of targeted change achieved can be used to determine the applicable progress status category, as both are equal to 0.0%. Because zero is less than 10% in magnitude and, even when statistical significance can be tested, zero cannot be statistically significant at the 0.05 significance level, the objective is classified as showing LITTLE OR NO DETECTABLE CHANGE.

### Percentage change from baseline for population subgroups

As learned from analyses related to the Healthy People 2020 Final Review (13), there are limitations to examining progress by population subgroups using the percentage of targeted change achieved, especially for groups that have already met or exceeded the target at baseline. Therefore, it may be more appropriate to assess progress by population subgroups using the percentage change from baseline as an alternate or supplementary measure to the percentage of targeted change achieved, allowing for comparisons between groups regardless of where they started the decade relative to the target.

## Measuring Health Disparities

In Healthy People 2030, as in Healthy People 2020 and 2010, disparities are operationalized as (absolute) differences, percentage differences, or ratios relative to a reference point, regardless of the social, economic, or environmental disadvantage of the groups being compared (9,10). Comparisons among population subgroups can be conducted using several choices for the reference point—for example, the Healthy People 2030 target, the total population, the group with the largest share of the population, or the group with the most favorable rate (or, when a decrease is desired, least adverse)—which has implications for the size and direction of disparity (10,14,15). As mentioned previously, comparisons with the Healthy People 2030 target may not be meaningful for population subgroups because Healthy People 2030 targets are set based on the total population—a weighted average of the subgroup rates—and some groups may already have exceeded the target at baseline (6). Comparisons with the total population rate may be inconclusive because, when examining changes over time, it can be difficult to distinguish the effects of changes in group rates from changes in the relative sizes of the groups in the population. Comparisons with the group with the largest share of the population may not be meaningful when, in many cases, smaller population groups achieve better health outcomes. Consequently, in Healthy People 2030, as in 2020 and 2010, disparities are relative to the most favorable (or, when a decrease is desired, least adverse) group rate that is observed among the subgroups for a given population characteristic in the population template (for example, by sex, race and ethnicity, or family income; see Table A).

### Disparities at a single timepoint

The following sections provide formal mathematical definitions corresponding to the disparities measures used in Healthy People 2030. Table C provides an overview of the constructs used in disparities measurement.

#### Notation

Let R_1_,R_2_,…,R_K _denote the group-specific rates for population subgroups g = 1,2,…,K. Let R_(1) _≤ R_(2) _≤ … ≤ R_(K)_ denote their ordered values, from smallest to largest. Using this notation, for an objective expressed in terms of an adverse outcome or condition that is to be decreased, the reference rate R_ref _(the least adverse group rate) is equal to the lowest rate R_(1)_, and the highest rate R_(K)_ is the most adverse group rate. On the other hand, for an objective expressed in terms of a favorable outcome or condition to be increased, R_ref = _R_(K) _(the most favorable group rate), and R_(1) _is the least favorable group rate. Let R_ave _denote the average rate of the K - 1 groups other than the group that achieved the reference rate R_ref_, calculated as:

R_ave_ = (R_(1)_ + R_(2)_ + ⋯ + R_(K − 1)_)/(K − 1) or R_ave_ = (R_(2)_ + R_(3)_ + ⋯ + R_(K)_)/(K − 1)

when the reference rate R_ref _is the highest rate, R_(K)_, or the lowest rate, R_(1)_, respectively.

#### Handling ties

To avoid ties between groups, unrounded values for rates are used in Healthy People 2030 disparities calculations. When two group rates are tied even after their unrounded values are compared, the tie is resolved using their unrounded SEs, when available, as follows:

- When a decrease is desired, a tie for the r^th^ smallest value, R_(r) = _R_(r + 1)_, with r = 1,2,…, or K - 1, is resolved using the group with the smaller unrounded SE as the group that achieves the r^th^ smallest rate R_(r)_.
- Conversely, when an increase is desired, a tie for the r^th ^largest value, R_(r - 1) = _R_(r),_ with r = K,K - 1,…, or 2, is resolved using the group with the smaller unrounded SE as the group that achieves the r^th^ largest rate R_(r)_.

In the unlikely event that the unrounded SEs corresponding to the tied group rates, when available, are also tied, or when SEs are not available, the group that achieves the r^th^ smallest (respectively, r^th^ largest) rate R_(r)_ is defined to be the group with the larger share of the total population.

#### Between-group measures

In Healthy People 2030, differences between each population subgroup rate and the reference rate are measured as absolute differences, whereas ratios are expressed as ratios of the larger rate to the smaller rate, which remain greater than or equal to one (directional ratios). In Healthy People 2020, only the between-group ratios were calculated (2). Even though between-group rate differences cannot be used for direct comparisons across objectives that are tracked using different measurement units, they remain useful for tracking absolute changes in disparities over time in the original units of measurement and can supplement findings based on the rate ratios (16). As a result, they have been added to the suite of disparities measures for Healthy People 2030.

##### Between-group rate difference and between-group rate ratio

The rate difference RD_g_ and rate ratio RR_g_ are used for between-group comparisons and assess the absolute difference and directional ratio, respectively, between the group-specific rate R_g_ and the reference rate R_ref_:

R D_g_ = |R_g_ − R_ref_| and R R_g_ = max R_g_ / R_ref_ , R_ref_ / R_g_ , g = 1 , 2 , … , K

The rate difference RD_g _remains nonnegative (absolute value of the simple difference in the rates). For the rate ratio RR_g,_ note that regardless of whether the objective is expressed as a favorable outcome to be increased, in which case RR_g_ = R_ref /_R_g_, or as an adverse outcome to be decreased, in which case RR_g_ = R_g /_R_ref_, the value will remain greater than or equal to one.

#### Overall measures

Whereas between-group measures allow detailed comparisons to the reference group rate for all subgroups within a population domain (sex, race and ethnicity, education, etc.), overall measures can be useful for quantifying the overall extent of disparity across all groups within that domain and provide a broad overview (3,10).

##### Maximal rate difference and maximal rate ratio

The maximal rate difference (MRD) and maximal rate ratio (MRR) are overall measures of disparity based on estimates of the highest and lowest rates among the population subgroups of interest. These measures were both used in Healthy People 2020 (4).

MRD is the difference and MRR is the ratio between the highest and lowest rates. Regardless of the desired directionality of the objective, they are defined as:

M R D = R_(K)_ − R_(1)_ and M R R = R_(K)_ / R_(1)_

##### Summary rate difference and summary rate ratio

The summary rate difference (SRD) and ratio (SRR) are also overall measures, comparing the reference rate R_ref _to the average rate R_ave_ for all the groups other than the reference group for the given population characteristic. The SRR was introduced in Healthy People 2020 and extends the Healthy People 2010 Index of Disparity, a special case of the SRR when objectives were (re-) expressed in terms of adverse outcomes or conditions to be reduced (4). For Healthy People 2030, the SRR is supplemented by the SRD, an absolute measure, to allow for both absolute and relative assessments of summary disparity. Because the SRD and SRR compare the reference rate with the average rate for all the other groups for a given population characteristic, their variability is reduced in comparison with the MRD and MRR, respectively, which compare the two extreme rates (most and least favorable, or least and most adverse) (3).

SRD is the absolute difference and SRR the directional ratio between R_ref_ and R_ave_:

S R D = |R_ave_ − R_ref_| and S R R = max R_ave_ / R_ref_ , R_ref_ / R_ave_

###### Considerations in Disparities Measurement

No single measure serves as the gold standard in the measurement of health disparities. Additionally, the importance of considering multiple measures and multiple types of health disparities, like absolute versus relative, between-group versus overall, and maximal versus summary measures, to provide more context for health disparities assessment is well established. Consequently, Healthy People 2030 methodology expands on Healthy People 2020 to allow for the examination of health disparities at a point in time and changes in disparities over time using all six measures above. Specifically, the between-group rate difference and summary rate difference, counterparts on an absolute scale to the between-group rate ratio and summary rate ratio on a relative scale, have been added to the suite of measures considered in 2030 compared with 2020 (so that each measure on a relative scale has a corresponding measure on an absolute scale).

The constructs used in disparities measurement in Healthy People 2030 are summarized in Table C.

Table C

Overview of disparities measurement in Healthy People 2030

Construct | Formula | Absolute or relative | Between-group or overall | Maximal or summary | Notes
Population subgroup rates | R_1_,R_2_,…,R_K_ | … | … | … | Group-specific rates are indexed by g = 1, 2, …, or K. Any ties in ranking are resolved using unrounded estimates and standard errors, when available, as described in “Methods.”
Ordered group rates (smallest to largest) | R_(1) _≤ R_(2) _≤ … ≤ R_(K )_ | … | … | … | Group-specific rates are indexed by g = 1, 2, …, or K. Any ties in ranking are resolved using unrounded estimates and standard errors, when available, as described in “Methods.”
Reference rate | R_ref_ _=_ R_(1)_ if decrease desired | … | … | … | If decrease is desired, the reference rate is the lowest group rate.
Reference rate | R_ref_ _=_ R_(K )_ if increase desired | … | … | … | If increase is desired, the reference rate is the highest group rate.
Average rate for all K – 1 groups other than the group that achieved the reference rate | . R_ave_ = (R_(2)_ + R_(3)_ + ⋯ + R_(K)_)/(K − 1) if decrease desired | … | … | … | Average rate for all K–1 groups other than the group with the lowest rate.
Average rate for all K – 1 groups other than the group that achieved the reference rate | R_ave_ = (R_(1)_ + R_(2)_ + ⋯ + R_(K − 1)_)/(K − 1) if increase desired | … | … | … | Average rate for all K–1 groups other than the group with the highest rate.
Between-group rate difference | RD _g_ _ = \| _ R _ref − _ R _g _ _\|_ | Absolute | Between-group | … | Measures the absolute difference between the reference and the group-specific rates for g = 1, 2, …, or K; remains greater than or equal to 0.
Between-group rate ratio | RR_g = max {_R_ref / _R_g ,_R_g / _R_ref }=_ R_g / _R_ref _If decrease desired_=_ R_ref_ _/ _R_g_ If increase desired | Relative | Between-group | … | Measures the directional ratio between the reference and the group-specific rates for g = 1, 2, …, or K; remains greater than or equal to 1.
Maximal rate difference | MRD = R _(_ _K _ _) − _ R _(1)_ | Absolute | Overall | Maximal | Measures the difference between the highest and lowest group rates; remains greater than or equal to 0.
Maximal rate ratio | MRR = R _(_ _K _ _) / _ R _(1)_ | Relative | Overall | Maximal | Measures the ratio of the highest to the lowest group rates; remains greater than or equal to 1.
Summary rate difference | SRD = _\| _R_ref − _R_ave_ _\|_ | Absolute | Overall | Summary | Measures the absolute difference between the reference rate and the average rate for all K–1 groups other than the group with the reference rate; remains greater than or equal to 0.
Summary rate ratio | SRR_ = max {_R_ref / _R_ave_ _,_R_ave_ _/ _R_ref }=_ R_ave_ _/ _R_ref _If decrease desired_=_ R_ref_ _/ _R_ave _If increase desired | Relative | Overall | Summary | Measures the directional ratio between the reference rate and the average rate for all K–1 groups other than the group with the reference rate; remains greater than or equal to 1.
Percentage change from baseline for disparitiesmeasure M | Percentage change in M from baseline= [(Most recent M value)/(Baseline M value)] • 100 | Relative | … | … | Quantifies the percentage change from baseline for measure M, where M is a between-group rate difference or ratio, the maximal rate difference or ratio, or the summary rate difference or ratio.
See footnotes at end of table.
Categories of change in disparities measure M over time | M is narrowing if the percentage change in M from baseline is less than 0 and statistically significant (when applicable), or the percentage change in M from baseline is less than or equal to –10%. | Relative | … | … | Statistical significance of the percentage change from baseline (when applicable) is assessed as described in the Appendix: Measures of Variability.
Categories of change in disparities measure M over time | M is showing little or no detectable change if the percentage change in M from baseline is not statistically significant (when applicable), or the percentage change in M from baseline is greater than –10% and less than 10%. | Relative | … | … | Statistical significance of the percentage change from baseline (when applicable) is assessed as described in the Appendix: Measures of Variability.
Categories of change in disparities measure M over time | M is widening if the percentage change in M from baseline is greater than 0 and statistically significant (when applicable), or the percentage change in M from baseline is greater than or equal to 10%. | Relative | … | … | Statistical significance of the percentage change from baseline (when applicable) is assessed as described in the Appendix: Measures of Variability.

… Category not applicable.

NOTES: Standard errors and 95% confidence limits are derived using resampling/bootstrap, as described in the Appendix: Measures of Variability, for the following constructs: the ordered population subgroup rates and their corresponding ranks; the reference rate and the average rate for all K–1 groups other than the group that achieved the reference rate; the between-group rate differences and ratios; the maximal rate difference and ratio; and the summary rate difference and ratio.

SOURCE: National Center for Health Statistics, Healthy People 2030 database.

### Changes in disparities over time

Changes in disparities over time in Healthy People 2030 will be assessed primarily on a relative scale to allow for direct comparisons between the multiple health disparities measures—although changes over time could be assessed on an absolute scale when only considering a single measure, such as the SRR in the Healthy People 2020 Final Review (17,18). Specifically, the percentage change from baseline allows for direct comparisons of the relative magnitude (and direction) of the change in disparities regardless of the measure used—for example, by calculating the percentage agreement among various overall measures of health disparities (3), such as the MRD, MRR, SRD, and SRR, which are summarized in Table C.

The percentage change from baseline in a given disparities measure M, for example, RD_g_, RR_g_, MRD, MRR, SRD, or SRR, is given by:

Percentage change in M from baseline = [(Most recent M value)/(Baseline M value) − 1] · 100

Disparities may be classified as “narrowing,” showing “little or no detectable change,” or “widening” between the baseline and most recent timepoints, depending on the magnitude of the percentage change from baseline as well as its statistical significance (when applicable) (3); see below and Table C. In Healthy People 2030, for a given disparities measure M, those categories of change in disparities over time are defined as in 2020:

- Disparities measure M is said to be narrowing when the percentage change in M from baseline is negative and statistically significant (when applicable) or when the percentage change is less than or equal to –10%.
- Disparities measure M is said to be showing little or no detectable change when the percentage change in M from baseline is not statistically significant or when the percentage change is between –10% and +10%.
- Disparities measure M is said to be widening when the percentage change in M from baseline is positive and statistically significant (when applicable) or when the percentage change is greater than or equal to +10%.

The assessment of statistical significance of the percentage change from baseline is detailed in the Appendix: Measures of Variability.

### Measurement of variability for disparities measures

To account for (a) the uncertainty in the ranking of the group rates from smallest to largest, (b) the variability in the reference group rate, and (c) the correlations among the ordered group rates, which impact the disparities measures described above, SEs and 95% confidence intervals (CIs) are derived using a resampling/bootstrap procedure, as detailed in the Appendix: Measures of Variability. Similar procedures have been employed in Healthy People 2010 for the Index of Disparity (11), which, as mentioned previously, is a special case of the SRR when objectives are (re-)expressed in terms of adverse outcomes or conditions to be reduced, as well as for disparities measures used in the National Cancer Institute’s HD*Calc software (19–21).