# Introduction

Established in 1979, Healthy People is an initiative of the U.S. Department of Health and Human Services that provides science-based, 10-year national objectives with numerical targets for improving the health of all Americans. For every decade since Healthy People 2000 (launched in 1990), the Healthy People initiative has also included an overarching goal related to health disparities. For Healthy People 2030, the disparities-related goal is to “Eliminate health disparities, achieve health equity, and attain health literacy to improve the health and well-being of all” (1).

This report focuses on describing Healthy People 2030 measurement practices for progress toward target attainment and the elimination of health disparities, comparing them with those that were in place in Healthy People 2020 (2–4). In addition, this report highlights the strengths and limitations of the Healthy People 2030 measurement practices and provides a methodological reference upon which future publications and analyses may expand further.

## Vision, Mission, and Overarching Goals

The framework for Healthy People 2030, which includes a vision, mission, and overarching goals, serves to provide context and rationale for the initiative. The vision of Healthy People 2030 is “A society in which all people can achieve their full potential for health and well-being across the lifespan.” Its mission is “To promote, strengthen, and evaluate the nation’s efforts to improve the health and well-being of all people” (1).

The overarching goals for Healthy People 2030 are to:

- Attain healthy, thriving lives and well-being free of preventable disease, disability, injury, and premature death.
- Eliminate health disparities, achieve health equity, and attain health literacy to improve the health and well-being of all.
- Create social, physical, and economic environments that promote attaining the full potential for health and well-being for all.
- Promote healthy development, healthy behaviors, and well-being across all life stages.
- Engage leadership, key constituents, and the public across multiple sectors to take action and design policies that improve the health and well-being of all.

## Objectives and Targets

Healthy People 2030 includes three types of objectives. Most objectives are core objectives, which are objectives that reflect high-priority public health issues and are associated with evidence-based interventions. Core objectives have valid, reliable, nationally representative data, including baseline data from no earlier than 2015 and an expectation of at least two follow-up data points during the Healthy People 2030 decade. In addition, all core objectives include targets for the decade. (These objectives were called measurable objectives in Healthy People 2020.) Healthy People 2030 also includes developmental objectives, which represent high-priority public health issues that are associated with evidence-based interventions but do not yet have a reliable data source and baseline data, and research objectives, which represent public health issues with a high health or economic burden or significant disparities between population groups but do not yet have evidence-based interventions (5). The methods outlined in this report apply only to core objectives and do not apply to developmental and research objectives.

The inclusion of quantifiable, 10-year targets has distinguished Healthy People from most other federal health indicator initiatives. Each of the 359 core objectives in Healthy People 2030 has an associated target generally set by topic area workgroups consisting of federal and nonfederal policy and subject matter experts using the baseline value for the total population for each objective and one of six target-setting methods: percent improvement; percentage point improvement; projection; minimal statistical significance; consistency with national programs, regulations, policies, or laws; and maintain baseline (6).

## Progress Toward Target Attainment

The examination of data relative to targets is critical to the usefulness of Healthy People, as targets communicate policy expectations and expert or evidence-based recommendations to a wide range of stakeholders. Targets offer a marker for assessing progress for each objective individually or for groups of objectives (including the initiative as a whole). The primary measure for assessing progress in Healthy People, the “percentage of targeted change achieved,” was first introduced in Healthy People 2010 and will continue to be used in Healthy People 2030. More detail is provided in the Methods section.

## Population Template

The standard data template shown in Table A, also referred to as the population template, is generally used for all population-based objectives in Healthy People 2030, although variations exist. Data are shown when collected, analyzed, and available from the data source for these groups and the applicable presentation criteria are met. If data for a particular demographic group are not collected, analyzed, or available, or if data for that group are suppressed because they fail to meet the applicable criteria for statistical reliability, data quality, or confidentiality, the Healthy People website cites one of these explanations for the reason data are not shown. Data presentation standards applicable to National Center for Health Statistics data systems are detailed in previous reports (7,8).

Table A

Healthy People 2030 standard population template

Population categories^1, 2^ | Population categories^1, 2^
Total | Health insurance status
Sex | Insured
Male | Private
Female | Public
Race and ethnicity | Uninsured
American Indian or Alaska Native only | Geographic location or region
Asian only | Metropolitan
Native Hawaiian or Other Pacific Islander only | Nonmetropolitan
Black or African American only | Marital status
White only | Married or cohabiting partner
Two or more races | Divorced, separated, or widowed
Hispanic or Latino | Never married
Not Hispanic or Latino | Country of birth
American Indian or Alaska Native only, not Hispanic or Latino | United States
Asian only, not Hispanic or Latino | Outside United States
Native Hawaiian or Other Pacific Islander only, not Hispanic or Latino | Veteran status
Black only, not Hispanic or Latino | Veteran
White only, not Hispanic or Latino | Nonveteran
Two or more races, not Hispanic or Latino | Disability
Age group (standard groups by data system) | People with disabilities
Educational attainment | People without disabilities
Less than high school | Sexual orientation
High school | Straight
Some college or associate’s degree | Straight, male
4-year college degree or more | Straight, female
Family income (percentage of poverty threshold) | Gay or lesbian
Less than 100% | Gay, male
100%–199% | Gay or lesbian, female
200%–399% | Bisexual
400% or more | Bisexual, male
| Bisexual, female
| Gender identity (standard groups by data system)

1 If data are not collected, analyzed, available, or presented for a particular demographic group by a data source, a symbol or acronym (DNC [Data for specific population not collected], DNA [Data have not been analyzed], DSU [Data do not meet the criteria for statistical reliability, data quality, or confidentiality]) will be displayed to indicate the reason data are not shown.

2 Categories and demographic groups may vary from this template, and additional categories and demographic groups may be included on a case-by-case basis.

NOTE: People of Hispanic origin may be of any race.

SOURCE: National Center for Health Statistics, Healthy People 2030 database.

Additionally, in Healthy People 2030, health disparities are assessed for all applicable groups in the population template, marking an evolution from 2010 and 2020, when disparities were only assessed for selected population characteristics when applicable (specifically sex, race and ethnicity, educational attainment, family income, geographic location, and disability status).

## Progress Toward the Elimination of Health Disparities

Healthy People 2020 and 2030 define health disparity as “a particular type of health difference that is closely linked with social, economic, and/or environmental disadvantage” (9). Population groups more adversely affected by health disparities are those who have systematically experienced greater obstacles to health based on characteristics that have been historically linked to discrimination or exclusion, such as race, ethnicity, religion, socioeconomic status, sex, age, mental health, disability, sexual orientation, gender identity, and geographic location.

In Healthy People 2030, as in 2020 and 2010, disparities are operationalized as measurable quantities, such as (absolute) differences, percentage differences, or ratios relative to a reference point, regardless of social, economic, or environmental disadvantage of the groups being compared. As in previous Healthy People reports of a similar nature (3,4), this report focuses on the operationalization rather than the conceptualization of health disparities measurement. Continuing the practice from Healthy People 2020, a suite of measures provides a comprehensive presentation of findings related to health disparities, with the number of measures expanded from four in Healthy People 2020 to six in 2030.

Briefly, the Healthy People 2030 suite of measures includes between-group and overall measures assessed in absolute and relative terms. For any given population characteristic, the six disparities measures used in Healthy People 2030 are:

### Between-group measures

- Between-group rate difference—The absolute difference between the reference and comparison group rates.
- Between-group rate ratio—The ratio between the reference and comparison group rates, defined so that its numerator is larger than its denominator.

### Overall measures

- Maximal rate difference—The absolute difference between the highest and lowest group rates.
- Maximal rate ratio—The ratio of the highest to the lowest group rates.
- Summary rate difference—The absolute difference between the reference group rate and the average rate of all other subgroups.
- Summary rate ratio—The ratio between the reference group rate and the average rate of all other subgroups, defined so that its numerator is larger than its denominator.

The above six measures are presented in detail in the Methods section, with further discussion about each measure’s strengths and weaknesses in the Discussion section.

Progress Toward Target Attainment and Eliminating Health Disparities

Assessment of progress toward target attainment for Healthy People 2030 objectives focuses on the total targeted population—because that is the basis for target setting for each objective—and uses the “percentage of targeted change achieved” for objectives moving toward their targets. The “percentage change from baseline” can also be calculated for all measurable objectives with a baseline and at least one follow-up data point, regardless of their targets or whether the change is in the desired direction. Progress toward target attainment for population subgroups in Healthy People 2030 may also be assessed, but because some groups may have started the decade closer or farther from the target compared with the total population, progress is more meaningfully assessed in relation to each group’s baseline value (without considering the target).

Analyses of health disparities at any given point in time consist of comparisons among population subgroups without reference to or consideration of the Healthy People 2030 baseline or target values. Progress toward the Healthy People 2030 overarching goal of eliminating health disparities and achieving health equity is assessed as a percentage change over time relative to each objective’s baseline disparities, for each of the applicable population characteristics in the population template. Even though related, analyses of progress and disparities in Healthy People 2030, as described here, are operationalized as distinct analyses that both fall under the purview of the initiative.