# References

1 U.S. Department of Health and Human Services, Office of Disease Prevention and Health Promotion. Healthy People 2030 framework. 2023. Available from: https://health.gov/healthypeople/about/healthy-people-2030-framework.
2 National Center for Health Statistics. Healthy People 2020 final review. 2021. DOI: 10.15620/cdc:111173.
3 Huang DT, Bassig BA, Hubbard K, Klein RJ, Talih M. Examining progress toward elimination of racial and ethnic health disparities for Healthy People 2020 objectives using three measures of overall disparity. National Center for Health Statistics. Vital Health Stat 2(195). 2022. DOI: 10.15620/cdc:121266.
4 Talih M, Huang DT. Measuring progress toward target attainment and the elimination of health disparities in Healthy People 2020. Healthy People Statistical Notes, no 27. Hyattsville, MD: National Center for Health Statistics. 2016. Available from: https://www.cdc.gov/nchs/data/statnt/statnt27.pdf.
5 U.S. Department of Health and Human Services, Office of Disease Prevention and Health Promotion. About the objectives. Available from: https://health.gov/healthypeople/objectives-and-data/about-objectives.
6 Hubbard K, Talih M, Klein RJ, Huang DT. Target-setting methods in Healthy People 2030. Healthy People Statistical Notes, no 28. Hyattsville, MD: National Center for Health Statistics. 2020. Available from: https://www.cdc.gov/nchs/data/statnt/statnt28-508.pdf.
7 Parker JD, Talih M, Malec DJ, Beresovsky V, Carroll M, Gonzalez JF Jr, et al. National Center for Health Statistics data presentation standards for proportions. National Center for Health Statistics. Vital Health Stat 2(175). 2017.
8 Parker JD, Talih M, Irimata KE, Zhang G, Branum AM, Davis D, et al. National Center for Health Statistics data presentation standards for rates and counts. National Center for Health Statistics. Vital Health Stat 2(200). 2023. DOI: 10.15620/cdc:124368.
9 U.S. Department of Health and Human Services, Office of Disease Prevention and Health Promotion. Health equity and health disparities environmental scan. 2022.
10 Keppel K, Pamuk E, Lynch J, Carter-Pokras O, Kim I, Mays V, et al. Methodological issues in measuring health disparities. National Center for Health Statistics. Vital Health Stat 2(141). 2005.
11 National Center for Health Statistics. Appendix A: Technical appendix. Healthy People 2010 final review. 2011.
12 Keppel K, Garcia T, Hallquist S, Ryskulova A, Agress L. Comparing racial and ethnic populations based on Healthy People 2010 objectives. Healthy People Statistical Notes, no 26. Hyattsville, MD: National Center for Health Statistics. 2008. Available from: https://www.cdc.gov/nchs/data/statnt/statnt26.pdf.
13 National Center for Health Statistics. Healthy People 2020 progress by population group. Healthy People 2020 final review. 2021. DOI: 10.15620/cdc:111173.
14 Harper S, King NB, Meersman SC, Reichman ME, Breen N, Lynch J. Implicit value judgments in the measurement of health inequalities. Milbank Q 88(1):4–29. 2010.20377756
15 Penman-Aguilar A, Talih M, Huang D, Moonesinghe R, Bouye K, Beckles G. Measurement of health disparities, health inequities, and social determinants of health to support the advancement of health equity. J Public Health Manag Pract 22(Suppl 1):S33–S42. 2016.26599027
16 Asada Y. On the choice of absolute or relative inequality measures. Milbank Q 88(4):616–22. 2010.21166871
17 National Center for Health Statistics. Healthy People 2020 overview of health disparities. Healthy People 2020 final review. 2021. DOI: 10.15620/cdc:111173.
18 National Center for Health Statistics. Healthy People 2020 progress table. Healthy People 2020 final review. 2021. DOI: 10.15620/cdc:111173.
19 Ahn J, Harper S, Yu M, Feuer EJ, Liu B. Improved Monte Carlo methods for estimating confidence intervals for eleven commonly used health disparity measures. PLoS One 14(7):e0219542. 2019. DOI: 10.1371/journal.pone.0219542.
20 National Cancer Institute. Health disparities calculator version 3.0.0. Bethesda, MD. Available from: https://seer.cancer.gov/hdcalc/.
21 Breen N, Scott S, Percy-Laurry A, Lewis D, Glasgow R. Health disparities calculator: A methodologically rigorous tool for analyzing inequalities in population health. Am J Public Health 104(9):1589–91. 2014.25033114
22 National Cancer Institute. Joinpoint Regression Program, Version 5.0.2. 2023.
23 Kim HJ, Fay MP, Feuer EJ, Midthune DN. Permutation tests for joinpoint regression with applications to cancer rates. Stat Med 19(3):335–51. 2000.10649300
24 Burton DC, Kelly A, Cardo D, Daskalakis D, Huang DT, Penman-Aguilar A, et al. Principles of health equity science for public health action. Public Health Rep 139(3):277–83. 2024. DOI: 10.1177/00333549231213162.38044623
25 The International Center for Equity in Health. Equiplot. Available from: https://www.equidade.org/equiplot.
26 Casella G, Berger R. Statistical inference. Boca Raton, FL: CRC Press. 2024.
27 DiCiccio TJ, Efron B. Bootstrap confidence intervals. Stat Sci 11(3):189–228. 1996.
28 Tukey JW. Exploratory data analysis. Vol 2. Reading, MA: Springer. 1977.