# Appendix: Measures of Variability

## Standard Error and Statistical Significance of the Percentage Change From Baseline

Let m_t _denote the most recent value and m_0_ the baseline value for a given rate or measure M. Using this notation, the percentage change from baseline is given by:

100 · (m_t_ − m_0_)/(m_0_)

In Healthy People 2020, the standard error (SE) of the percentage change from baseline, used to assess statistical significance of movement for objectives that are moving away from their baselines and targets (4), is derived using the following approximation:

S E ((m_t_ − m_0_)/(m_0_)) = (|m_t_ − m_0_|)/(m_0_) sqrt((S E^2^ (m_t_) + S E^2^ (m_0_))/((m_t_ − m_0_)^2^) + (S E^2^ (m_0_))/(m_0_^2^)) [1]

A closely related approximation, derived from observing that the SE of (m_t − _m_0_)/m_0 _is the same as the SE of m_t /_m_0_, is the following:

S E ((m_t_)/(m_0_)) = ((m_t_)/(m_0_)) sqrt((S E^2^ (m_t_))/(m_t_^2^) + (S E^2^ (m_0_))/(m_0_^2^)) [2]

Using the logarithmic transformation allows correction for potential lack of normality in the underlying measure and results in the following approximation:

S E (ln [(m_t_)/(m_0_)]) = (S E (m_t_ / m_0_))/(m_t_ / m_0_) = sqrt((S E^2^ (m_t_))/(m_t_^2^) + (S E^2^ (m_0_))/(m_0_^2^)) [3]

The significance of the percentage change from baseline can be evaluated by testing the null hypothesis that

(m_t_ − m_0_)/(m_0_) = 0 , that (m_t_)/(m_0_) = 1 , or that ln [(m_t_)/(m_0_)] = 0.

The resulting test statistics are:

z_1_ = (sgn (m_t_ − m_0_))/(sqrt((S E^2^ (m_t_) + S E^2^ (m_0_))/((m_t_ − m_0_)^2^) + (S E^2^ (m_0_))/(m_0_^2^)))

z_2_ = (1 − (m_0_ / m_t_))/(sqrt((S E^2^ (m_t_))/(m_t_^2^) + (S E^2^ (m_0_))/(m_0_^2^)))

z_3_ = (ln [m_t_ / m_0_])/(sqrt((S E^2^ (m_t_))/(m_t_^2^) + (S E^2^ (m_0_))/(m_0_^2^)))

respectively, where sgn (m_t_ − m_0_) = + 1 when m_t >_ m_0_, 0 when m_t = _m_0_, and –1 when m_t <_ m_0_.

Those three test statistics are such that z_2 ≤ _z_1 _and z_2 ≤ _z_3_. As a result, when compared with the critical value 1.959964, say, to assess significance at the 0.05 level of an increase from baseline (m_t >_ m_0_), significance based on z_2 > _1.959964 also implies significance based on z_1 > _1.959964 and z_3 > _1.959964, whereas z_2 ≤ _1.959964 fails to reject the null hypothesis in cases where either z_1 > _1.959964 or z_3 > _1.959964 (or both) can be true. As a result, a significance test based on z_1_ or z_3_ is more powerful (more likely to reject the null hypothesis that the percentage change is zero when it truly is nonzero) than one based on z_2_ for assessing increase from baseline (Figure) (26). Additionally, as seen in the graph for the range -10 to 10 in the Figure, a test based on z_2_ is more biased than a test based on either z_1_ or z_3_, in that the probability of rejecting the null hypothesis when the percentage increase is larger than zero but less than five drops below the 0.05 significance level of the test, meaning that it would be more likely to reject the null when it is true than when it is false in those cases, which is suboptimal.

Figure

Power to detect nonzero percentage differences from baseline for three significance tests of the percentage change from baseline

The Figure shows the power to detect nonzero percentage differences from baseline for three significance tests of the percentage change from baseline. The first panel shows that a significance test based on z1 or z3 is more powerful than one based on z2 for assessing increase from baseline. The second panel shows that a test based on z2 is more biased than a test based on either z1 or z3.

Unlike the z_2-_based test, tests based on z_1_ and z_3_ also have symmetric power functions around the null hypothesis of a zero percent change, meaning that they are equally powerful in detecting, say either a 10% increase or a 10% decrease from baseline. Additionally, for all practical purposes, the latter appear to be equivalent, as seen in the overlapping power functions in the Figure. As a result, either could be used for statistical testing in Healthy People 2030, without any practical drawback of using one versus the other. Still, because it remains more convenient to describe change over time in the underlying rate using the percentage change from baseline, significance testing in Healthy People 2030 for the percentage change from baseline is based on the two-sided test for z_1_, namely z_1 > _1.959964 or z_1 < −_1.959964.

For objectives that are moving away from their baselines and targets, significance is based on the one-sided test of the magnitude |z_1_| of z_1_, namely |z_1_| > 1.644854, and is used to determine the GETTING WORSE or LITTLE OR NO DETECTABLE CHANGE categories (4).

On the other hand, for assessing changes in disparities over time, the percentage change from baseline in measure M is more readily expressed in terms of the ratio m_t /_m_0 _, because m_t _and m_0_ are themselves differences (RD_g_, MRD, SRD) or ratios (RR_g_, MRR, SRR) in the underlying group rates; as a result, significance testing for changes in disparities over time is based on the two-sided test for z_3_, namely z_3 < −_1.959964 or z_3 > _1.959964 (3).

### Confidence Intervals for the Percentage Change From Baseline

Any of the SE approximations in formulas 1–3 above could be used to construct a 95% confidence interval (CI) for the percentage change from baseline. For consistency with the use of z_1 _or z_3 _for significance testing, as described above, a symmetric (Wald) CI can be obtained from equation 1 as follows:

100 · ((m_t_ − m_0_)/(m_0_)) ± 1.959964 · S E ((m_t_ − m_0_)/(m_0_))

whereas an asymmetric (lognormal) CI can be obtained from equation 3 as follows:

100 · exp [ln ((m_t_)/(m_0_)) ± 1.959964 · S E (ln ((m_t_)/(m_0_)))] − 1

## Standard Error and Statistical Significance of the Percentage of Targeted Change Achieved

Using the notation from the previous section, the percentage of targeted change achieved is:

100 · (m_t_ − m_0_)/(m_T_ − m_0_)

where m_T _denotes the Healthy People 2030 target. The SE of the percentage of targeted change achieved, used to assess statistical significance of movement for objectives that are moving toward their targets (4), is derived using the following approximation:

S E ((m_t_ − m_0_)/(m_T_ − m_0_)) = |(m_t_ − m_0_)/(m_T_ − m_0_)| sqrt((S E^2^ (m_t_) + S E^2^ (m_0_))/((m_t_ − m_0_)^2^) + (S E^2^ (m_0_))/((m_T_ − m_0_)^2^))

For objectives that are moving toward their targets, the significance of the percentage of targeted change achieved can be evaluated by testing the null hypothesis that

(m_t_ − m_0_)/(m_T_ − m_0_) = 0

against the one-sided alternative

(m_t_ − m_0_)/(m_T_ − m_0_) > 0.

The resulting test statistic is:

z_4_ = (1)/(sqrt((S E^2^ (m_t_) + S E^2^ (m_0_))/((m_t_ − m_0_)^2^) + (S E^2^ (m_0_))/((m_T_ − m_0_)^2^)))

Values of z_4_ _>_ 1.644854 determine the IMPROVING category, whereas values of z_4_ such that 0 _≤ _z_4_ _≤_ 1.644854 determine the LITTLE OR NO DETECTABLE CHANGE category (4).

### Computation of Standard Errors and Confidence Intervals for Disparities Measures

In contrast with Healthy People 2020 (4), where SEs were calculated using formula-based approximations that assumed independence between the groups and CIs were Wald CIs (of the form Estimate ± 1.959964 • SE), SEs and CIs for all six disparities measures in Table C are evaluated using a resampling/bootstrap procedure, to better account for the uncertainty in the ranking of the groups from smallest to largest, the variability in the reference group rate, and the correlations among the ordered group rates R_(1) _≤ R_(2) _≤ … ≤ R_(K)_ .

The resampling/bootstrap procedure uses the rate and SE for each population subgroup to randomly draw each group rate 25,000 times according to a normal distribution, truncated to ensure resampled values remain in the desired range (for example, 0–100 for percentages). Based on each set of simulated group rates, 25,000 estimates of the relative rankings as well as the reference rate and each of the six disparities measures are generated. Subsequently, the frequency distribution of these estimates is used to estimate the empirical SEs and 95% CIs. For the CIs, the lower and upper limits are set to the corresponding 2.5th and 97.5th percentiles (27). For the SE, the interquartile range (75th percentile minus 25th percentile) is divided by 1.349 to provide a robust estimate that is less sensitive than the average squared deviation from the sample mean to aberrant random draws (28). Similar procedures have been employed in Healthy People 2010 for the Index of Disparity (11), a special case of the SRR, as well as for disparities measures used in the National Cancer Institute’s HD*Calc software (19,20).

## Statistical Significance Testing for Disparities Measures

As in Healthy People 2020, statistical significance of disparities measures in Healthy People 2030 is based on one-sided tests. For the between-group rate difference, maximal rate difference, and summary rate difference, the statistic for testing the null hypothesis that the difference is zero versus the alternative hypothesis that it is positive is z = difference/SE_difference_, which is compared with the normal critical value 1.644854 to determine significance at the 0.05 level. For the between-group rate ratio, maximal rate ratio, and summary rate ratio, which are such that their numerators are larger than their denominators, the statistic for testing that the ratio is one versus the alternative that it is larger than one is z = ln(ratio)/SE_ln(ratio)_, where the natural logarithm ln(ratio) = 0 if and only if ratio = 1. The standard errors SE_difference _and SE_ln(ratio)_ are obtained from the resampling/bootstrap procedures described previously.

Note that the bootstrapped SE for the reference rate will differ from the SE for the rate of the group that was identified as the reference group. Similarly, the bootstrapped SEs for the lowest and highest rates will differ from the SEs for the rates of the groups that achieved the lowest and highest rates, respectively. As a result, the use of resampling/bootstrap to assess the variability and statistical significance of the Healthy People 2030 disparities measures may lead to seemingly contradictory findings if not interpreted with care.

For example, suppose group A, identified as achieving the lowest rate for a given objective, has a rate of 39.0% with SE = 3.000, whereas group C, identified as achieving the highest rate, has a rate of 46.5 with SE = 6.000. Assuming a decrease is desired for this objective, the lowest rate attained by group A is the reference rate, and the between-group difference between groups C and A is 7.5 percentage points. The SE of the difference is approximately 6.708, whether calculated using the bootstrap- or the formula-based approach (namely, sqrt(3.000^2^ + 6.000^2^) = sqrt(45) ), and, therefore, the difference is not statistically significant (z score is approximately 7.5/6.708 = 1.118 < 1.644854). However, if one were to take into account an intermediate rate between the lowest and highest, then the maximal rate difference, which remains 7.5 percentage points, may very well become statistically significant if its bootstrap-based SE is small enough, say 4.500 (z score is 7.5/4.500 = 1.667 > 1.644854). This situation could occur in a bootstrap sample when the intermediate rate was statistically near the highest rate (say, group B has rate 45.5 and SE = 2.000), reducing the uncertainty regarding the highest rate being 46.5, regardless of which group achieved it. (In this scenario, the bootstrap-based SE for the highest rate would be approximately 3.570 instead of 6.000.)

An Excel-based tool (the Health Disparities Tracking Tool) illustrating the Healthy People 2030 methodology for estimating SEs and CIs and statistical significance testing, and allowing users to replicate the methodology and examples shown in this report is available for download from: https://www.cdc.gov/nchs/healthy_people/hp2030/hp2030-methods.htm.