# Front Matter

## Dedication

This report is dedicated to Richard J. Klein, M.P.H. (August 26, 1948–December 22, 2022)

Richard’s public health statistics career spanned 45 years, first as a federal employee with the National Center for Health Statistics’ (NCHS) Division of Vital Statistics and the Office of Analysis, Epidemiology, and Health Promotion (now the Division of Analysis and Epidemiology); and then, after his retirement, as a contractor with NCHS. From 1992 to 2011, Richard was the Chief of the Health Promotion Statistics Branch, where he led the tracking and analysis of progress toward national health promotion and disease prevention objectives for the Healthy People initiative. Following his retirement in 2011 until his untimely passing in 2022, he continued to make major contributions to this and other national health monitoring initiatives as a statistical consultant to NCHS. Richard continually demonstrated his unwavering commitment to NCHS and public health as he worked with colleagues to promote high-quality methods and data for monitoring the nation’s health. He was esteemed by many throughout CDC and HHS for his remarkable knowledge of measures and data systems (including for the Healthy People initiative over its five iterations), his ability to present complex information thoughtfully and practically, his dedication to the importance of measuring progress on Healthy People’s goals to eliminate health disparities and achieve health equity, and his ever-constructive and diplomatic nature in navigating sometimes contentious decisions about measures and data sources. This report reflects many of Richard's insights during the development of initial drafts. He was a treasured colleague and a true friend; he will genuinely be missed.

National Center for Health Statistics

Brian C. Moyer, Ph.D., Director

Amy M. Branum, Ph.D., Associate Director for Science

Division of Analysis and Epidemiology

Division of Analysis and Epidemiology

Irma E. Arispe, Ph.D., Director

Kimberly A. Lochner, Sc.D., Associate Director for Science

For answers to questions about this report or for a list of reports published in these series, contact:

Information Dissemination Staff

National Center for Health Statistics

Centers for Disease Control and Prevention

3311 Toledo Road, Room 4551, MS P08

Hyattsville, MD 20782

Tel: 1–800–CDC–INFO (1–800–232–4636)

TTY: 1–888–232–6348

Internet: https://www.cdc.gov/nchs

Online request form: https://www.cdc.gov/info

For e-mail updates on NCHS publication releases, subscribe online at: https://www.cdc.gov/nchs/updates/.

## Acknowledgments

Makram Talih completed this work under a contract with Windsor Group, LLC, a CDC/NCHS contract holder. All authors gratefully acknowledge the current and former programmers and analysts of the Health Promotion Statistics Branch at NCHS for their technical and statistical expertise, as well as for their critical review of the data that were used for the examples. We are also thankful for the organizational support of the Division of Community Strategies, Office of Disease Prevention and Health Promotion, U.S. Department of Health and Human Services.