# Conclusion

Although this pilot study demonstrated the possibility of fielding an in-home biological measures collection study and collecting adequate blood and urine samples from adults who have already completed a major health survey in their homes, even in the middle of a pandemic, some unique challenges were presented. Once participants started the examination, nearly all provided both a blood and urine sample, nearly all those samples were shipped successfully, and most were tested successfully. Using the lessons learned, many, if not most of the problems encountered in this pilot study could be prevented in a scaled-up version of the study. One exception is overcoming the relatively low Sample Adult participation rate. That challenge remains central to this project and will likely remain so in future studies of this kind.