# Limitations

Because Sample Adults who completed the interview in a language other than English or who required a proxy were not eligible, this study provides no information about the best ways to facilitate the participation of such members of the population. Doing so would be vital if these protocols became an integral part of the NHIS, in order to ensure the study results were representative of the full U.S. population.

Information about the concerns or reasons for nonparticipation was not collected for the 52.2% of Sample Adults who gave permission for their contact information to be passed on to the schedulers but never spoke with a scheduler.

Also, there is no information about if or how the characteristics of the FRs who responded to the post-field period FR survey differ from FRs who were invited but did not respond. It is also unknown if or how the Sample Adults who were eligible for NHIS FHS and who were interviewed by those responding and nonresponding FRs differed, and if or how the agreement percentage differed between those two groups of Sample Adults.

It is unclear from this pilot study if eliminating the gap between the introduction and appointment scheduling would increase or decrease participation. Although it would streamline the process because the interviewer is already speaking to the Sample Adult, the interviewer has developed rapport with the Sample Adult, and the Sample Adult is not given a chance to forget why they agreed to schedule an appointment or to avoid the scheduler’s calls, the delay between the interview and scheduling might give the Sample Adult time to recover from the exhaustion of the interview, consequently increasing their willingness to participate when asked at that later date. Also, NHIS FRs already reported “satisficing scheduling,” also called “ghosting.” In these cases, the Sample Adult schedules an appointment just to get the FR to leave, but then does not show up at the scheduled time. Sample Adults displayed this behavior sometimes in this pilot study, and it might happen more frequently if the Sample Adult were pressured to schedule at the time of the NHIS interview.

Because the visit durations were calculated using instrument time stamps, those durations do not include the approximately 5–10 minutes the health representative spent at the household before opening and after closing the instrument. That time was spent greeting, screening, and consenting the participant, and unpacking and repacking the equipment. The visit durations also do not include any time the health representative spent collecting the body measurements or urine before opening the instrument.

NCHS had almost no direct contact with ExamOne, Westat’s subcontractor who made the scheduling calls and conducted the home examinations, so NCHS could not learn directly from ExamOne about their capabilities or reasons for decisions. As a result, some factors that may have impacted a Sample Adult’s willingness to participate are unknown, as is their impact on the results. For example, NCHS had no ability to provide direct feedback or direction to ExamOne, which would presumably not be the case if NCHS brought this project to scale. The ability to provide direct feedback also could potentially help raise response rates. Also, as mentioned in the sections “NHIS FHS Interagency Agreement” and “External Contractors,” ExamOne phlebotomists were not accustomed to gaining cooperation from study participants. In addition, ExamOne schedulers had an unknown degree of experience in recruiting for research studies. Both of these factors may have had a negative impact on participation rates.

The COVID-19 pandemic had period effects whose exact extent is unknown. For example, it is unknown how COVID-induced stress might have reduced the likelihood that Sample Adults agreed to participate at the end of the NHIS interview or when the scheduler called, or even answered the phone when the scheduler called.