# Feasibility of Implementing Protocols With Full NHIS Sample

## Bringing Project to Scale: Eliminating Many Identified Problems

If the collection of biological measures was made an integral part of NHIS, many of the challenges encountered in this pilot study would presumably be eliminated. In other words, NCHS knew in advance that certain operational parameters, discussed in the following sections, would be preferable, but it was not possible to implement them in this pilot study because of the constraints inherent in pilot studies.

The first step would be to identify one set of staff members to take primary responsibility for inviting and recruiting the Sample Adults to participate. The primary operational problem encountered in this study was that no contractor and, so, no individual staff member, took primary responsibility for recruitment. If NCHS decided to make biomeasure collection a core element of NHIS, willingness to take full responsibility for, a history of success in, and a robust plan for recruitment for examinations following survey interviews should be a central requirement of all contractors responsible for the parts of the operations that precede the start of the home examination.

With such a contractor(s) in place, many of the operational limitations encountered in this study could be avoided. First, the staff issuing the introduction would be fully invested and integrated into the study, with no limitations on their involvement due to authorizing legislation, for example. As a result, instead of being required to read a scripted introduction, they would be free to use their best judgement based on their observations of the Sample Adult, experience, and expertise, to craft their own pitch, as many of the FRs suggested during the FR debriefing. Such an approach is the standard for NCHS surveys and would be consistent with the procedures used by NHIS FRs when introducing the NHIS interview, and by NHANES interviewers when introducing the NHANES study (12,13). Second, as an integrated step within the survey participation experience, there would be no need to mention the contractors collecting the biological measures by name, even if they are a separate entity from the NHIS interviewer contractor. This might reduce respondent privacy concerns and increase agreement to be contacted. Third, there would be time for, and no restrictions placed on, the training provided to all study staff on introducing and explaining the purpose and value of the study and the many benefits of participation, and on skills and strategies for convincing reluctant participants. Such training could be extensive and involved, using adult learning best practices including role plays, similar to NHIS’s standard initial and refresher training. Incorporating this training into the initial training for the project, instead of sending it as a memo mid-field period, was also suggested by the FRs during the focus groups. NHANES provides robust training for all household operations staff, which includes both field interviewers and phone line staff, at initial and annual trainings, and sometimes at additional midyear trainings. All of these improvements would likely increase the chances of higher agreement rates.

The second step would be to increase the planning period and investment in infrastructure. Having more than 12 weeks to plan would bring a number of advantages besides the extra time to plan and implement the training described previously. First, with more time, and presumably additional funding, it would be possible to create a more extensive IT infrastructure to enable immediate and possibly online appointment scheduling at the time of the interview that can be accessed by all study staff at all times. NHANES has a system with some of this capability. NHANES field interviewers can see the MEC schedule while they are still at the home but must call a scheduler to make the appointment. Given that NHIS FHS scheduling staff were never able to make phone contact with 52.2% of incompletes, making it possible for the FR to schedule the appointment while already speaking to the Sample Adult could substantially raise overall completion rates. Such a system would also eliminate the need for recruitment specialists to bring a separate scheduling staffer into the phone call with the participant who has agreed to schedule an appointment. Such a system might also reduce the delay between the interview and the home examination. Second, with more time and additional funding, it would be possible to implement an online participant portal that Sample Adults could use to schedule and view appointments, view examination results, and communicate with study staff about scheduling or any other concerns. Such a system would eliminate scheduling barriers to participation. In addition, the personalized passcode provided to the Sample Adult during the introduction could be a kind of proxy advance incentive for the results they would obtain by participating. Third, it would be possible to automate the generation of appointment reminders for both health representatives and participants. This might reduce the need for reschedules. Fourth, additional laptops, one for the presenter’s display and one for the trainee to practice entering data, could be provided if the health representative training is still virtual. If the assessment is still virtual, the assessor could have multiple views and a full field of vision via a shared health representative application screen and a camera and tripod to observe the health representative’s work with the examination equipment.

A longer planning timeline would also offer opportunities for other improvements. It would make it possible to incorporate information about the biological measure collection step into the survey advance materials and the survey website, which would underscore its legitimacy and importance. A longer planning timeline would provide more time to develop and test recruitment strategies and techniques. More time would also be available before data collection began to test planned communication systems between the laboratory and study management, and to test the biospecimen processing and test results reporting procedures with a set of blood and urine samples. This would make it possible to catch any errors, such as missing test codes in the laboratory requisition forms, and to ensure that the laboratory had all the participant information needed to calculate all planned results. Such pretesting would minimize the number of re-collects, and consequent delays in results reporting.

Extending the timeline would also increase the contractor pool to include those without an existing NCHS-approved IT security authorization boundary but the ability, given enough time, to obtain one. As a result, NCHS could choose from a wider selection of contractors. The staff would also presumably be directly employed and managed, rather than subcontracted. This would allow for closer monitoring, management, corrective feedback, and, if needed, termination if the health representative is unable to follow study protocols, meet quality expectations, or is unwilling to meet the hours commitment. This might also enable the requirement that staff enter their availability in the project calendar at least a month in advance, which could make scheduling easier.

## Bringing Project to Scale Not During a Public Health Emergency

If this project were brought to scale at a time without a pandemic or other public health emergency, other improvements would be possible. Health representative training and assessment could occur in person, which is preferable for both learning and robust assessment of skill readiness. In-person training helps ensure that health representatives are fully engaged with the materials, equipment, and systems throughout the entire training process. In-person training also allows the trainers to monitor trainee progress and intervene if they notice that a trainee is having difficulty.

Fewer staffing problems among the health representatives and laboratory staff would also be likely. This increased staffing would likely increase the availability of appointments at times convenient for participants, and reduce laboratory errors. Also, Sample Adults might be more willing to welcome a stranger into their home to conduct the examination.

## Lessons Learned

In future similar studies, implementing the following suggestions might make the invitation to participate more effective:

- Add information about the study to the survey respondent website and advance letter, or send a separate letter about the study. Either approach could help legitimize the study.
- Allow interviewers to use their expertise and the rapport they develop with the respondent to customize the introduction. If the introduction must be scripted, shorten it, ask the question sooner, emphasize that the respondent can refuse to do any part, and provide a better explanation of the value of participation.
- Instruct all staff to omit the name of the contractors working on the study, if any. All study staff should instead be referred to as “NHIS staff” or something similar.
- Conduct methodological experiments to determine optimal incentive size. Consider adjusting incentive size to account for differences in period conditions, timing of the follow-up relative to the main study, sample composition, and examination components between such experiments and the study being planned.
- Hire a separate sales or marketing contractor to identify stories and strategies for explaining the value of the study and of participation. Bringing on board such expertise and incorporating their language into the staff training and respondent materials could help motivate respondents who might otherwise refuse.

In future similar studies, implementing the following suggestions might increase the percentage of eligible cases who schedule appointments:

- Expand the calling window and increase the number of mandated phone contact attempts beyond three tries over 5 days and beyond two follow-up contact attempts in 3 days. Besides providing more opportunities for connection, such an expansion will give the schedulers and recruitment specialists greater flexibility in scheduling their contact attempts to coincide with respondents’ preferred time slots, increasing the likelihood of reaching the respondent. NHIS interviewers have a month to attempt to schedule the interview. NHANES field interview staff usually schedule MEC appointments immediately after the home interview, but at times may not be able to. NHANES household operations staff work diligently with participants to set up appointments before the end of examinations at that location.
- Provide extensive training in selling the study and refusal conversion to all study staff tasked with contacting Sample Adults to schedule appointments. This training should use modern adult learning modalities, including extensive roleplays, and should provide trainees with extensive language for explaining why participation in the study is exciting and important. The competency assessment should evaluate this skill. Such training may help prevent refusals and motivate participation.
- Assess the skills of recruitment specialists.
- Increase or change the incentive structure to attract those who have been difficult to reach or reluctant to participate. A larger incentive might help, as might including an unloaded gift card with the follow-up (noncontact and refusal) mailings, and a note reminding the participant that $75 would be added to the card after the visit. Alternatively, this card could be included in a separate mailing sent after the first. Having the gift card in hand may motivate some respondents who may be otherwise reluctant to participate. An incentive could also be provided at the time of scheduling in the form of a gift code. However, this recommendation would increase costs.
- Add in-person, nonresponse follow-up to the contact attempt protocol, if cost and staffing allow.

If maximizing the number of participants who fast before their appointment is a goal of future studies—unlike in this study—then implementing the following strategies might increase the percentage of participants who fast:

- Ensure that project health representatives are available to conduct home examinations before 10:00 a.m. because most people will find it easier to fast for 8 hours if the appointment is early in the morning.
- Provide an additional incentive greater than $75 for participants who fast at least 8 hours. It may be helpful to include information in the study brochure about the added benefit to the participant if fasting, but this strategy might also discourage some people from participating entirely.

In future similar studies, implementing the following strategies might decrease problems with biospecimen packaging, shipping, handling, analysis, and results reporting.

Biospecimen collection, processing, and analysis is a highly technical and regulated industry, so a high level of planning, research, and validation is necessary even for a pilot study, even when using a national laboratory that is CLIA-certified. Quest Diagnostics’s systems and procedures, which are fine-tuned to support ongoing processing in a healthcare setting, were not easily modified to support the privacy of participant information required in a research study.

In future studies, to minimize ethics review delays, study planners should consider the following steps:

- Check if any test result requires mandatory reporting to public health authorities, if confidentiality is promised.
- Inquire and determine if the laboratory requires signed HIPAA authorization forms from study participants or if a waiver of HIPAA authorization will meet the laboratory compliance and legal requirements. If a waiver will meet the compliance, obtain the waiver as soon as possible during the development phase.
- Inquire and determine if the laboratory has regulatory or corporate reporting and record retention requirements that conflict with study protocol or legislative requirements. If so, determine if mitigation strategies can be put in place.
- Check the list of all types of demographic participant data required by the laboratory to perform the tests and calculate the results. Ensure that all the information can be passed to the laboratory by gaining all necessary ERB approvals and participant consents.

In future studies, to minimize problems due to late delivery of biosamples to the laboratory, study planners should consider the following:

- Encourage participants to avoid scheduling on Saturday (because there is no Sunday delivery for FedEx shipments collected or sent on Saturday), and in the evening if it will not be possible for the health representative to deliver the package to the FedEx location before it closes. Doing so will maximize the chances that the blood and urine samples will arrive at the laboratory within their stability window (for example, 48 hours after specimen collection for blood hemoglobin). Note that even early evening appointments could be problematic if the participant is late, the examination runs long, or the participant lives in a rural location with limited FedEx service or in an area with heavy evening traffic.
- Inform participants whose availability is limited to these times that they may not receive all of their test results when booking the appointment.

In future studies, to maximize the study staff’s ability to monitor the biospecimen results, study planners should consider the following:

- Use a laboratory with a results portal or system that the project staff can access to identify and quickly resolve sample issues to ensure laboratory testing is completed within the stability window.
- Use a laboratory that can provide results electronically.

In future studies, to minimize health technician errors, study planners should consider the following:

- Use electronic, not paper, requisition forms, if possible. Auto-populate the electronic requisition form to minimize health representative input errors. If paper forms must be used, consider providing paper job aids to the health representatives, such as checklists or an annotated version of a completed laboratory requisition form. Provide additional practice during training in completing the requisition forms correctly.
- Provide paper job aids with explanatory photos for tasks that the health representative completes after they have logged out of the computer and left the home, such as biospecimen packing and shipping instructions.
- Require health representatives to review the aspects of the study’s examination procedures with a manager, if their first scheduled appointment is many weeks following the training. This could help prevent some of the form and packaging problems that were more common among health representatives who conducted their home examinations a relatively long time after the training.

In future studies, to increase the likelihood that health representatives transmit their cases in a timely manner, consider paying them for hours needed to work with the project helpdesk to resolve issues. In future studies, to minimize delays in mailing the final reports, ensure that the plan for transmitting final reports of findings to the medical officer meets confidentiality requirements and test the system before the beginning of the data period.

## Problems That Cannot Be Solved by Scaling Up

Even if this project was brought to scale, it would be very difficult to ensure that NHIS sample sizes in each area were large enough to support 20–30 hours of work per health representative per week. NHANES sampling design enables this staffing model, but NHIS’s sampling design cannot. In many sparsely populated areas of the country, identifying such a large NHIS sample would not be feasible. As a result, it would still not be possible to require staff in many areas to commit to working that many hours per week. As a result, it would not be possible to gain the benefits of such a model. Staff working that frequently can conduct home examinations regularly and begin conducting home examinations shortly after training. Such staff are better prepared to follow standardized study protocol, consequently reducing error, and improving data quality. Also, the more health representatives who are able to commit more hours to working on the study in advance, the greater the availability of appointments at times convenient for participants. This would also reduce scheduling conflicts due to health representatives’ other projects or jobs and reduce the need for reschedules. Reschedules due to cases not yet loaded on the health representatives’ laptop would also likely be reduced, because they would presumably have more availability and scheduled time to meet and review assigned cases each week with their supervisor. In such a scenario, there would presumably be health representatives able to fill in for health representatives who are unable to keep scheduled appointments.