# Successes and Challenges of Biospecimen Packaging, Shipping, Handling, Analysis, and Results Reporting

## Operational Successes

Of the 175 participants who submitted a blood sample, 86.3% received complete results (n = 151), 12.0% received partial results (n = 21), and 1.7% did not receive results because their blood could not be tested (n = 3) (Table 2). Of the 171 participants who submitted a urine sample, 90.0% received complete results (n = 154), 5.8% received some of the results (n = 10), and only 4.1% did not receive any results (n = 7). The reasons for incomplete and missing results are discussed in “Minor Operational Challenges.”

Because the biospecimen collection kits supplied by Westat were all complete, health representatives had all the labeling and packing supplies they needed to correctly label, package, and ship the blood and urine collected in each home examination.

As shown in Table 16, most of the samples arrived at the laboratory within either 1 day (44.9%, n = 79) or 2 days (29.0%, n = 51), but 25.0% (n = 44) of the samples arrived between 3 and 5 days after collection. One sample was shipped 7 days late and arrived 10 days after collection. When the samples arrived at Quest Diagnostics, the staff did not routinely check the stability window of the samples. It may be that some samples that were tested for blood hemoglobin and urine glucose should not have been tested, and the results, while within the normal range, may not have been accurate. Westat mailed 135 (76.7%) of the final report of findings to the participants within 30 days of the home examination.

Table 16

Number of days between home examination and arrival of biospecimens at laboratory

Duration (days) | Number | Percent
1 | 79 | 44.9
2 | 51 | 29.0
3–5 | 44 | 25.0
10 | 1 | 0.6

SOURCE: National Center for Health Statistics, National Health Interview Survey Follow-up Health Study, 2021.

The low volume of critical values—only three in three separate participants—matched NCHS and Westat’s expectations and were handled according to protocol. Each of the three critical values identified by Quest Diagnostics was relayed to the medical officer on the day it was identified, meeting the requirements of the CLIA regulations. In two of the three cases, the medical officer was able to speak with the participant about the critical value. While the medical officer was unable to reach the third participant even after multiple contact attempts, the participant’s final report of findings was generated early and sent to the participant’s address on file.

## Minor Operational Challenges

### Packaging, Shipping, Handling, and Analysis Problems

Five causes were identified for incomplete urine test results received by 17 participants and incomplete blood test results received by 24 participants. Problems with laboratory requisition forms were the cause of most of the missing or incomplete urine (10 of the 17 urine samples) and blood (20 of the 24 blood samples) test results. Specifically, 3 of the 10 incomplete urine test results, all 7 of the missing urine test results, 18 of the 21 incomplete blood results, and 2 of the 3 missing blood results could have been completed had it not been for problems with the lab requisition forms. Completing the paper requisition form was the most challenging aspect of the biospecimen collection for the health representatives. Even so, it did not present a major problem.

The health representatives encountered no other challenge regularly; the other four problems were rare. Packaging problems accounted for three of the partial urine test results, centrifuging problems accounted for three of the partial blood test results, laboratory error accounted for three of the partial urine test results and one of the missing blood test results, and inadequate urine quantity was the cause of one set of incomplete urine test results.

#### Incomplete or inaccurate laboratory requisition forms

Of the 17 urine samples with partial or missing results and 24 blood samples with partial or missing results, 58.8% (n = 10) and 83.3% (n = 20), respectively, could have had complete results if the requisition forms had been completed and delivered correctly.

Three of the 10 urine samples with partial test results were incomplete due to missing information on the urine requisition form. Among the seven urine samples with no test results, the laboratory did not receive the urine requisition form with the urine sample in two cases, and the health representative incorrectly filled out the form in five cases. Of these five cases, two had an incorrect sample ID number on the form, and three did not have marked off which tests were to be performed.

Two of the three blood samples with no test results could not be tested because the health representative did not complete the requisition form correctly.

Eighteen of the 21 blood samples with partial results were missing the bilirubin test due to a missing code on the blood requisition form. Quest Diagnostics does not test the blood for direct bilirubin unless that code is listed on the form, even though their pricing for the comprehensive metabolic panel includes direct bilirubin. However, the direct bilirubin test code was not printed on the blood requisition form. This problem was discovered 1 month into the study when the first results were transmitted to Westat, by which time 13 samples had already been delivered to the laboratory. Although new forms were ordered once the problem was identified and the health representatives were instructed to write in the direct bilirubin test code until the new forms arrived, in five additional cases the health representative did not write in the code, so those five blood samples were also missing the direct bilirubin test result.

#### Packaging problems

Three of the 10 urine samples with incomplete results could only be tested for some analytes because either the urine vial leaked during transport (n = 2) or the yellow-top urine vial was not received by the laboratory (n = 1).

#### Problems with centrifuging blood serum

In this study, blood glucose testing was performed on the serum. Separating the serum from the red cells within 1 hour of collection was a priority for accurate results. Three blood samples could only be tested for some analytes because the health representative did not centrifuge the serum separator tubes correctly or at all. As a result, these three samples had prolonged exposure to the red blood cells after collection, so the blood glucose test could not be run.

#### Laboratory error

Three of the 10 urine samples with incomplete test results were due to laboratory error. The laboratory misplaced one of the three blood samples that could not be tested at all. Three of the blood samples with incomplete test results for other reasons also had no hemoglobin test result because the stability window for hemoglobin was exceeded due to laboratory error. When the samples arrived at Quest Diagnostics, the staff did not routinely check the stability window of the samples. If the laboratory technologist received an abnormal value or had some other reason to investigate the results, the laboratory still did not check the collection time of the sample.

### Reporting Problems

#### Delay in sending final report of findings to NCHS

While 135 of the final reports of findings were mailed to the participants within 30 days of the home examination (76.7%), 41 of the final reports were sent more than 30 days after the home examination (23.3%). About one-half of the delayed reports were due to an unexpected change in the procedure for accessing the reports by the medical officer (n = 18). In the original plan, Westat was going to mail a package of paper copies of the reports to the medical officer so they would have them on hand in case a participant called with questions about their results. However, after preparing the first batch of final reports, Westat raised a confidentiality concern and suggested that the copies instead be provided to the medical officer electronically. Because these reports contained personally identifiable information, they needed to be stored on a restricted server, which the medical officer could not access from their telework location. As mentioned in “COVID-19-period Conditions,” the entire NCHS workforce was teleworking during the NHIS FHS field period. After it was decided that Westat would send NCHS the copies of the final reports electronically, it took just over 2 weeks for the medical officer to gain access to the NCHS-restricted server. As a result, the first set of 18 reports were mailed about 15 days later than planned; this was an inconvenience but not a major problem.

Another 18 of the final reports of findings were sent more than 30 days after the initial home examination because the participant was informed of a testing problem with the collected specimen and was offered a re-collect of one or more of their biospecimens, and the delay pushed out the mailing date past the 30 day-post-examination mark (10.2%). The final report of findings for the 29 cases offered a re-collect were only sent after the participant declined the re-collect, did not respond to three phone attempts, or agreed to the re-collect and Westat received the test results for the re-collected samples. A total of 27 cases were offered re-collects because of problems with biospecimen collection due to health representative or laboratory error. Seven of the potential re-collects were for urine only. Nine of the potential re-collects were for blood samples only. Re-collects of both blood and urine samples were offered to the remaining 11 of the 27 participants. Of the 27 re-collects offered, only 8 participants agreed to and provided a second sample. Five of the eight completed re-collects were for blood only, two were for urine only, and one was for blood and urine.

The last five of the final reports of findings were delayed for a variety of unrelated reasons (2.8%). One report was delayed because an ID was incorrectly recorded in the Quest Diagnostics computer system. Another delay was due to a urine sample not being collected but was assumed pending by Westat. That report was mailed 32 days after the home examination. One was an error with mailing the report, resulting in the report being sent 47 days after the examination. The report was recorded in the computer system as mailed although it had not been. Westat discovered the error during a quality control review of the files. One report was mailed initially 19 days after the examination but there was a change in address for the participant, so Westat sent a copy of the report to the new address 34 days after the examination. The most prolonged report delay was 97 days. This occurred because of an error in completing the requisition forms by the health representative that caused a delay in sample testing at Quest Diagnostics. In addition, the participant did not have any blood collected, which was not evident in the health representative’s examination documentation. These factors caused pending partial results for an extended time in the weekly laboratory file that Westat received from Quest Diagnostics.

#### Estimated glomerular filtration rate

The introduction to the NHIS FHS that the FR read to the Sample Adult mentioned sex and age but not race in the list of personal information that would be passed to the contractor if the Sample Adult agreed to participate. Therefore, race could not be passed on to the contractors. However, the formula used to calculate one blood test value, the estimated glomerular filtration rate (eGFR), depended, at the time, on the participant’s race. There was one formula for people who are Black or African American and one for people of other races. (More details are available from: https://www.kidney.org/kidney-topics/understanding-african-american-and-non-african-american-egfr-laboratory-results).

While the National Kidney Foundation and the American Society of Nephrology have since published a recommendation to use one equation that does not factor in race, two equations were still in use when the missing race variable problem was discovered on July 2, 2021, a month into the field period. At that point, it was too late to get permission from the NCHS Ethics Review Board to change the instrument to get permission from the participant to provide the contractor with the participant’s race. As a result, the value was calculated using both formulas and reported the results for Black or African American and non-Black or African American people on the final report of findings for each participant. This could have caused a problem for critical value reporting, had eGFR been included on the critical value reporting list, but it was not. See Appendix XVI for a sample final report of findings.

### Causes of Packaging, Shipping, Handling, Analysis, and Reporting Problems

The problems described in the previous sections were likely at least partially the result of other challenges encountered during the pilot study. Most of these underlying challenges were the result of the short duration and small pilot sample, and some were also the result of COVID-19-related conditions. These challenges were communication difficulties between the laboratory and Westat, the few cases available for some health representatives, health representative training limitations, and laboratory staffing shortages.

#### Communication difficulties between contractor and subcontractor

The bilirubin code, eGFR, and requisition form problems could have been avoided with more efficient communication between the subcontractor and contractor. Better communication about which tests needed their own code on the form could have ensured that the direct bilirubin code was printed in the forms initially distributed to the health representatives, and then all samples would have been tested for bilirubin. Better communication about the need for the participant’s race in order to report a single eGFR reference range for each participant could have enabled proactive planning for eGFR reporting. More prompt communication about requisition form errors (incorrect sample ID number or not all the required tests checked off) could have resulted in more samples being tested within the acceptable window. Also, when Westat learned in the second month of data collection that it could use Quest Diagnostics’s Quanum for Healthcare Professionals to monitor test results in near-real time, Westat was better able to address problems quickly. These problems might have been fixed sooner if Westat had been granted access to the system sooner.

#### Short timeline and absence of test run

The biospecimen analysis process was not tested before the field period began. A test set of blood and urine samples could have been, but they were not, sent to the laboratory along with the study’s requisition form and tested with the results sent electronically following planned study procedures. Had there been such a test run, the missing bilirubin code would have been noticed early and new forms with the correct direct bilirubin code could have been provided to the health representatives before the field period began.

#### Few cases available for some health representatives

Health representatives had less work than expected because fewer Sample Adults agreed to participate and schedule an appointment than expected. Also, the Sample Adults who scheduled appointments were not evenly distributed across the geographic areas of the pilot sample, so the work was not evenly distributed among the health representatives. As a result, some health representatives had few cases or conducted their home examinations a relatively long time after their training. Both factors could have contributed to their errors with the forms.

In general, health representatives who completed the greatest number of examinations had fewer data entry and procedural errors. The repetition associated with frequent examinations helped to reinforce the study procedures and led to increased proficiency. In contrast, health representatives who were assigned a small number of examinations may not have completed their first examination until weeks or even months after training. In this situation, ExamOne provided the health representative with a brief refresher of the study protocols, emphasizing areas where health representatives were most likely to encounter problems or deviate from the approved procedures, based on the problems encountered in the initial weeks of data collection. However, the health representatives who received this refresher training were not reassessed after receiving it.

#### Health representative training and assessment limitations

The paper requisition form was the most challenging aspect of the biospecimen collection for the health representatives. Although ExamOne and Quest Diagnostics routinely use paper requisition forms for most of their projects, every project has slightly different forms due to the type of samples being collected. This project’s form was very different from most requisitions that the health representatives had worked on previously. The training could have focused more on this aspect of the protocol by providing the health representatives with more opportunities to practice filling out the forms. The virtual format of the training, though not ideal, was not necessarily a barrier to including such practice. The kit could also have included a sample copy of the requisition form with instructions.

However, the virtual format did have other limitations. Because each trainee only had one laptop, and it was difficult to view two windows side by side, trainees could not easily view the trainer’s screen and practice entering data at the same time. There were also the unavoidable distractions of virtual training, conducted at a time when childcare options were limited due to the pandemic. In an effort to address the limitations of virtual training, Westat offered additional one-on-one training review and practice, but only four health representatives attended these sessions.

The virtual evaluations, conducted using smart phones or laptop computers that did not allow for an entire field of view, made on-the-spot correction difficult and may also have contributed to the error rate.

#### Laboratory staffing shortages

Quest Diagnostics staffing shortages, due to COVID-19 and routine staffing problems, may have caused delays in notifications of problems that could have been corrected, and testing accomplished, if Westat had been notified more quickly.