# Successes and Challenges of Conducting Home Health Examination

## Operational Successes

Once the participants gave consent for the examination, nearly all finished all parts of the examination protocol. As shown in Table 2, between 97% and 100% of participants who gave consent completed each of the blood pressure, height, weight, and waist circumference measurements, and provided adequate urine and venous blood samples to send to the laboratory.

For all but two of the incomplete components, the participants who did not complete a component were prevented from doing so by physical limitations. In only one case did a participant refuse the blood component partway through, and in only one case did a participant refuse the urine component. Three participants were unable to void, and six participants could only provide a partial urine sample. Of the 173 participants who provided a blood sample, 1.7% provided a partial sample (n = 3), and of the 171 participants who provided a urine sample, 4% provided a partial sample (n = 6).

The examinations were conducted according to protocol with little or no documented problems. No components were incomplete due to communication problems or equipment failure. The battery on the scale never ran out without a spare, and the blood pressure equipment functioned as intended in all examinations. Because the biospecimen collection kits supplied by Westat were all complete, health representatives had all needed supplies for each home examination’s blood and urine collection. Health representatives had and used all required personal protective equipment for each examination, and there were no reports of any participant or health representative infecting the other with COVID-19. All the Visa prepaid cards that the health representatives provided to participants worked correctly.

The duration of the examinations was within the promised range, about 1 hour, as stated on the informed consent form (Appendix XII), in nearly all cases (92.0%). About one-third of examinations took less than 30 minutes (34.7%). Examination durations, stratified by sex and age group separately and combined, are shown in Table 12. The median duration for the full examination was 34 minutes for the total sample, women and men. The median duration by age was 33 minutes for adults ages 18–34, 34 minutes for adults ages 35–64, and 36 minutes for adults ages 65 and older. A similar pattern and range were seen when men and women were examined separately.

Table 12

Duration of National Health Interview Survey Follow-up Health Study home examination components among adults who completed each component, by age and sex

Characteristic | Total for all examination components | | Urine | | Body measure | | Blood pressure | | Blood collection | | Check out
Characteristic | Median | Min, Max | Median | Min, Max | Median | Min, Max | Median | Min, Max | Median | Min, Max | Median | Min, Max
All | 34 | 20,69 | 5 | 0,29 | 3 | 1,15 | 9 | 1,19 | 7 | 1,31 | 5 | 2,26
Sex
Women | 34 | 20,66 | 4 | 0,14 | 3 | 1,15 | 9 | 2,16 | 7 | 1,21 | 5 | 2,22
Men | 34 | 21,69 | 5 | 0,29 | 3 | 1,14 | 9 | 1,19 | 6 | 1,31 | 5 | 2,26
Age
18–34 | 33 | 20,63 | 3 | 0,16 | 3 | 1,7 | 9 | 2,17 | 6 | 1,15 | 5 | 2,15
35–64 | 34 | 20,69 | 4 | 0,22 | 3 | 1,14 | 9 | 1,19 | 7 | 1,28 | 5 | 2,26
65 and older | 36 | 21,69 | 6 | 0,29 | 3 | 1,15 | 9 | 2,19 | 7 | 1,31 | 5 | 2,22
Women
18–34 (n = 20) | 32 | 20,61 | 2 | 1,7 | 3 | 2,7 | 9 | 2,14 | 6 | 1,15 | 4 | 3,12
35–64 (n = 39) | 34 | 20,66 | 4 | 0,14 | 3 | 1,8 | 9 | 4,16 | 7 | 2,16 | 5 | 3,17
65 and older (n = 21) | 38 | 22,59 | 6 | 1,12 | 3 | 1,15 | 9 | 2,14 | 7 | 3,21 | 5 | 2,22
Men
18–34 (n = 19) | 33 | 23,63 | 5 | 0,16 | 3 | 1,6 | 8 | 3,17 | 6 | 1,14 | 5 | 2,15
35–64 (n = 33) | 33 | 22,69 | 5 | 0,22 | 4 | 1,14 | 9 | 1,19 | 7 | 1,28 | 5 | 2,26
65 and older (n = 31) | 36 | 21,69 | 6 | 0,29 | 3 | 1,9 | 9 | 2,19 | 7 | 1,31 | 5 | 3,8

NOTE: Duration is measured in minutes.

SOURCE: National Center for Health Statistics, National Health Interview Survey Follow-up Health Study, 2021.

The schedulers were instructed to schedule the home examination as soon as possible. Table 13 shows the number of days between the NHIS interview and the completed home examination. Most examinations, 62.5% (n = 110), were conducted within 1 month following the interview, but 13.1% (n = 23) were conducted within 14 days of the NHIS interview. Although 37.5% (n = 66) were completed more than 28 days later, most of these (n = 51) were conducted within the next 2 weeks (5–7 weeks after the interview).

Table 13

Number of days between National Health Interview Survey interview and completed Follow-up Health Study home examination

Duration (days) after interview | Number | Percent
1–14 | 23 | 13.1
15–28 | 87 | 49.4
29–49 | 51 | 29.0
50 or more | 15 | 8.5

SOURCE: National Center for Health Statistics, National Health Interview Survey Follow-up Health Study, 2021.

As described in “Methods,” after completing the examination procedures, the health representative asked the Sample Adult a set of questions about their NHIS FHS experience. Most participants reported that the burden of participation was low, and that participation did not negatively impact their expectation of participation in a future similar study (Table 14). Among Sample Adults who completed a home examination, 75.0% (n = 132) said it was very easy to participate in the home visit, and 24.4% (n = 43) said it was easy. Only one participant said it was difficult; that participant had trouble scheduling an examination due to limited health representative availability. Additionally, 68.2% (n = 120) said it was very easy to get their questions answered, 19.3% (n = 34) said it was easy, and 12.5% (n = 22) said they did not have any questions. No participants said it was difficult or very difficult to get their questions answered. Of the 44 participants who completed the home visit, who reported in the post-examination survey that participating in the home visit was easy or difficult, and who were asked for suggestions for making the home visit easier and more convenient, two-thirds stated that they had no recommendations. Two participants, rather than providing a suggestion for improvement, noted that they appreciated the convenience of having a health representative come to their home. Of the small number of suggestions offered, all were related to scheduling. Nearly all 176 Sample Adults who completed a home examination responded that they would be very likely (64.2%, n = 113) or likely (34.7%, n = 61) to participate in a similar study in the future. Two participants (1.1%) reported they would be unlikely to participate in the future and none said they would be very unlikely.

Table 14

Burden of home visit and expectation of participation in future similar study among National Health Interview Survey Follow-up Health Study participants who completed home examination

Characteristic | Number | Percent
How easy or difficult was it for you to take part in this home visit?:
Very easy | 132 | 75.0
Easy | 43 | 24.4
Difficult | 1 | 0.6
Very difficult | 0 | 0.0
How easy or difficult was it to get your questions answered?:
Very easy | 120 | 68.2
Easy | 34 | 19.3
Difficult | 0 | 0.0
Very difficult | 0 | 0.0
Didn't have questions | 22 | 12.5
How likely or unlikely are you to participate in a studylike this in the future?:
Very likely | 113 | 64.2
Likely | 61 | 34.7
Unlikely | 2 | 1.1
Very unlikely | 0 | 0.0

NOTE: A total of 176 National Health Interview Survey Follow-up Health Study participants completed a home examination.

SOURCE: National Center for Health Statistics, National Health Interview Survey Follow-up Health Study, 2021.

In summary, the examination itself had no avoidable problems. A few participants had incomplete components of the examination (n = 15), and most of those were unable to complete the omitted components due to physical limitations (n = 13). No equipment failures, incomplete kits, faulty Visa prepaid cards, or COVID-19 transmission were reported, and examinations were completed in a timely manner. No problems or complaints were reported by Sample Adults during or after the examination visit concerning the health representatives who visited them.

## Minor Operational Challenges

### Data Entry Errors

As shown in Table 15, health representatives made data entry errors in a few cases. The health representative entered the incorrect number of urine vials in 5.1% of cases (n = 9), the incorrect number of blood tubes collected in 2.3% of cases (n = 4), the incorrect height in 3.4% of cases (n = 6), and the incorrect Visa card proxy ID in 2.8% of cases (n = 5). After Westat discovered these errors early in the field period and provided feedback, those health representatives did not repeat the error. To prevent these errors from recurring, ExamOne included reminder instructions in the weekly e-mail to the health representatives on these topics. A few of these data entry errors occurred later in the field period among different health representatives who had also, perhaps not coincidentally, completed the fewest examinations.

Table 15

Percentage of all completed National Health Interview Survey Follow-up Health Study examinations with data entry errors

Data entry error | Number | Percent
Incorrect number of urine vials | 9 | 5.1
Incorrect number of blood tubes collected | 4 | 2.3
Incorrect height | 6 | 3.4
Incorrect Visa card proxy ID | 5 | 2.8

NOTE: A total of 176 National Health Interview Survey Follow-up Health Study participants completed a home examination.

SOURCE: National Center for Health Statistics, National Health Interview Survey Follow-up Health Study, 2021.

### Short Blood Pressure Rest Period

While monitoring home examination time stamps, Westat project staff discovered early in the field period that some health representatives were either beginning the 5-minute rest period before opening the instrument or failing to observe the full rest period before taking the measurements. The ExamOne supervisor provided feedback to individual health representatives. In most instances, the health representatives reported they had followed the protocol but did not open the instrument before reading the talking points and beginning to time the rest period. Following this discovery, the weekly e-mail to health representatives included reminders to use the project smart phone to time the rest period and open the blood pressure instrument before starting the examination, including reading any talking points. This problem persisted among a minority of health representatives throughout the field period.

### Delayed Transmission

In about one-quarter of the cases with completed examinations (25.6%, n = 45), the health representative did not transmit their case data within a day after the appointment had occurred, as directed by the protocol. Westat and the ExamOne supervisors discovered these cases when reviewing the transmission report each day against the scheduled appointment list and contact effort reports. If they discovered that health representatives with appointments scheduled for the previous day had neither transmitted nor entered a note to indicate why the visit did not occur, the ExamOne supervisors followed up with the health representatives and provided a transmission reminder or guidance on how to document the incomplete visit, as needed. Even though ExamOne’s weekly project e-mail reminded the health representatives to transmit immediately after completing the appointment, and to alert their supervisor and schedule a remote session with Westat’s project helpdesk if they encountered any computer problems, the late transmission problem persisted throughout the field period. Health representatives were not paid for time spent working with the helpdesk. Late transmission is undesirable because it increases the chances of data loss, through theft or inadvertent destruction of the laptop.