# Successes and Challenges of Informing Sample Adult About Study and Related FR Tasks

## Operational Successes

The mean amount of time FRs spent reading the text describing NHIS FHS to the Sample Adult (121 seconds) was mostly higher than the expected duration (101 seconds). This indicates that FRs were not speeding through the NHIS FHS questions but reading them fully.

FRs were well prepared for their role, as defined by the U.S. Census Bureau. In the post-study survey of the FRs, 42.5% felt “very prepared to ask Sample Adults about the NHIS FHS” after their computer-based training, and 10.0% felt either “somewhat or very underprepared.” In the July focus group, FRs reported that they did not refer to the FAQs in the instrument because they already knew the answers from the training. They also reported that the brochure clearly explained the purpose and procedures of the study and answered the questions of respondents who had questions, although few did. FRs reported in both focus groups and the FR survey that the training was appropriate, thorough, clear, helpful, and high quality (7).

The instrument functioned as intended, and all Sample Adult demographic and contact preference information was shared with the contractor accurately, securely, and on schedule throughout the study period.

## Operational Challenges

As noted in the Methods section, the U.S. Census Bureau policy prevented FRs from taking any “substantive role” in this study. This introduced three key challenges. The first challenge was that the process of introducing the Sample Adult to the study and asking about their willingness to be contacted about it had to be embedded in the FR’s existing job of reading the text from the NHIS instrument and entering the Sample Adult’s answers. Second, that script had to include particular language that may have discouraged response. Third, FRs only received limited and late training in converting reluctant participants, and gaining cooperation for this study was never defined as part of their job, nor did they receive any incentive for gaining cooperation. Consequently, while FRs were well prepared for their defined role, their role limitations created challenges.

Operational challenges also arose from the pilot nature of the project: the delay between the FR obtaining the Sample Adult’s permission to be contacted and the opportunity to schedule the home visit, the credibility gap created by not mentioning FHS in the advance letter and on the NHIS website (see “Credibility and Integration With NHIS”), and limitations on the information that could be included in the brochure.

Two operational challenges arose as a result of the timing of the pilot study during the COVID-19 pandemic: the unusually high phone interview rate of NHIS in summer 2021 (9) and the unusually high rate of mental health difficulties and daily stress in the U.S. population (10). The second may have made the monetary incentive less effective than it would have been otherwise.

### Preprogramed Introduction Script

The U.S. Census Bureau’s requirements to script the process of asking the respondent if they would be willing to give permission to pass their information to the contractor and to include the sentence “The Census Bureau does not have a role in this study” may have contributed to the low response rate, individually or in combination. In addition, the mention of ExamOne in that script may also have also discouraged response. The requirement to script the interaction undermined a major advantage of timing the introduction to the study to coincide with the end of the Sample Adult interview—the chance to capitalize on the FR’s rapport with the respondent and their expertise in reading respondent cues and customizing the language accordingly. Even after FRs were allowed to use their expertise in converting reluctant participants, starting in the second month of the field period, they still could not use it until after they had read the prepared script in its entirety. The agreement rate increased from 29.6% in June to 38.9% in July, though it dipped again to 33.3% in August before rising to 37.7% in September. The rise between June and July may have been due at least partly to the new procedure but was likely also due to increased FR familiarity with the text and the increased in-person interview rate that month (see “High NHIS Phone Interview Rate in Summer 2021”).

In the first focus group, FRs suggested creative ways for revising the script, giving examples of how they would have used their skills and expertise to customize the introduction, had they been allowed to do so. In addition, FRs in the July focus group suggested that the introduction might have been more successful if it was shorter, got to the question sooner, and referenced the rest of the interview process (such as by acknowledging that it had already been long, and saying “we’re almost done”). They also suggested that the introduction should emphasize the information that the participant can refuse to do any part.

In the post-study survey, FRs also indicated that they felt the scripted introduction was too abrupt and did not adequately explain why the respondent should participate (7). In the post-study survey, only 39.4% of responding FRs said they never needed to rephrase the questions about being contacted for the study, while 50.7% of responding FRs said they sometimes needed to do so (7). More than one-quarter of responding FRs said they only sometimes could get through the introduction screens without being interrupted by the Sample Adult (7).

In addition, the inclusion of the sentence “The Census Bureau does not have a role in this study” and the explicit mention of ExamOne created a break between NHIS and FHS that contrasted the FR’s usual technique of maintaining momentum through the entire interaction to reduce breakoffs. By deliberately defining FHS as a separate project, participation became an “extra task” instead of an intrinsic part of NHIS. FRs mentioned this problem in the second set of focus groups (7).

The explicit mention of ExamOne had an uneven impact on privacy concerns among Sample Adults. In the first FR focus group, some noted that some Sample Adults were concerned about their data going to an external company, even though no respondent’s personally identifiable information ever left the systems and hardware within the NCHS IT security authorization boundary. In contrast, in the second round of focus groups, some FRs reported that the mention of the subcontractor’s name was reassuring to the respondent when the respondent was familiar with and had positive perceptions of ExamOne or Quest Diagnostics (7).

### FR Role Restrictions and Training Delays

The U.S. Census Bureau’s limits on FR involvement in FHS also negatively impacted the FR’s study-specific training. FRs only received permission, and guidance for converting reluctant participants during the second month of the study, and not during the initial computer-based training. This permission and training came through a memo, which did not provide FRs with an opportunity to practice the skills the way computer-based or role play-based training could have. Also, the memo could have been easily overlooked in an e-mail inbox.

In a later survey of FRs asking about their experiences working on NHIS FHS, 33.7% reported that they did not use or remember using this memo. This suggests that they may not have read the memo. Supporting evidence for this interpretation is that FRs rarely read the FAQs, and 29.5% of responding FRs said they did not use or did not remember using the FAQs when asked how helpful they were (7).

In the July focus group, FRs reported that most Sample Adults did not have questions, were not interested in seeing the brochure, and were not swayed by the brochure; they just refused. Also, FRs reported that because they already knew the answers to the questions in the FAQs from the training, they did not use the FAQs embedded in the instrument.

The memo training was also unspecific about the FR’s role. Most NHIS FR training is very clear about the FR responsibilities. In contrast, the memo introduction described its contents as “…some additional information that you can use to address respondent concerns about the follow-up study. If you feel that a respondent’s initial refusal might be converted using some of this additional information, we encourage you to do so…. Please use your own judgement as to whether additional efforts to convince respondents to participate is appropriate.” Gaining cooperation was never explicitly defined as part of the FR’s role.

Another possible consequence of the ambiguity about the FR's role, and the absence of any clear instruction or benefit to the FR for gaining agreement, was lack of FR commitment to gaining agreement. When asked if it would have been helpful to have the scheduler available on the phone to answer the Sample Adult’s questions and schedule the health visit on the spot, only 16.9% of responding FRs said “yes.” Another 32.4% responded “not sure” and 50.7% said “no.” The survey question was not clear, however, about who it would have helped to have the scheduler on the phone. As discussed in the next section, there are theoretical and practical reasons to believe that having a scheduler available at the time of the NHIS interview would have been helpful for gaining agreement to be contacted and perhaps for scheduling appointments. However, introducing an extra person and step into the NHIS interview process could have potentially disrupted the FR’s main goal of completing the NHIS interview.

### Credibility and Integration With NHIS

The absence of the study from the NHIS website also posed a challenge during the introduction stage. To avoid confusing and possibly even alarming most NHIS respondents, who were not included in this small pilot study, no information about NHIS FHS was added to the NHIS website. Also, the advance letter was not modified for this pilot study (see “Study Materials”). As a result, FRs could not refer the Sample Adult to the website or the advance letter for more information about FHS, which may have damaged the FR’s credibility, the legitimacy of the study, and the Sample Adult’s likelihood to agree to participate. These absences may have contributed to Sample Adults’ impressions that FHS was an extra burden, instead of an integral part of the NHIS participant experience.

### Limitations on Content in Initial Brochure

Because this was a pilot study with a convenience sample whose purpose was to learn whether NHIS respondents would be willing to participate in a home examination following their interview, the home examination anthropometry and blood pressure measurements and the biospecimen test results had no use beyond the pilot study. This would not be true in a full-scale implementation of the home examination procedures. This created a challenge for the content of the initial brochure, which was resolved by using deliberately vague language about the intended use of the data. Although this was necessary, it may have limited the effectiveness of the brochure. Two of the most frequently endorsed responses to the FR survey question about changes to the materials that would be helpful for convincing reluctant Sample Adults to participate were “Providing more detailed information about how the data will be used” (21.7%) and “Providing more information about how participation will benefit the Sample Adult” (25.1%).

### Timing of Introduction Relative to NHIS Interview

A related challenge resulting from the pilot status of this study was the lack of mention of the study in the advance letter. However, FRs were not uniform in their assessment of this timing issue. Some FRs suggested introducing the study earlier in the interview or in the advance letter so it was not unexpected (7). However, some FRs suggested delaying the introduction until a later date, noting that Sample Adults might be more willing to agree to be contacted after they had a break. Many participants considered the near hour-long NHIS interview to be very long already and were tired by the time it finished. This split perspective was reported in the responses of FRs to the post-survey question about whether it would be easier to convince Sample Adults to provide their contact information for FHS if they could have told them in advance about the study. The most frequently endorsed answer was “not sure” (50.0%), and the rest were split between “no” (27.8%) and “yes” (22.2%) (7).

### High NHIS Phone Interview Rate in Summer 2021

Two period effects added challenges. The low percentage of Sample Adult interviews completed in person for the main NHIS during the study introduction period (June–September 2021) (43.6%, see “Methods”) may also have contributed to the low agreement rate for FHS. FRs reported in the July 2021 focus group that it was easier for respondents to refuse to be contacted for NHIS FHS over the phone, while they were more likely to ask questions and agree to be contacted when the NHIS interview occurred in person. Although the Sample Adult in-person rate for NHIS rose between January and June 2021, it leveled off in June (42.5% in June, 46.4% in July, 42.8% in August, and 42.4% in September) (Table 7).

Table 7

Percentage of completed Sample Adult interviews conducted in person, by month, geographic area, and inclusion in 2021 National Health Interview Survey Follow-up Health Study sample

Sample characteristic | January | February | March | April | May | June | July | August | September | June–September
Total NHIS sample | 21.5 | 23.1 | 28.3 | 34.3 | 39.9 | 42.5 | 46.4 | 42.8 | 42.4 | 43.6
Census regional offices withNHIS FHS sample | 25.9 | 26.7 | 34.0 | 37.1 | 45.2 | 43.8 | 49.7 | 42.1 | 45.9 | 45.4
Primary sampling units notselected for NHIS FHS | 28.7 | 30.0 | 38.5 | 43.0 | 50.8 | 51.9 | 56.3 | 47.5 | 50.8 | 51.0
Primary sampling units selectedfor NHIS FHS | 22.0 | 21.5 | 26.5 | 28.5 | 35.6 | 29.6 | 38.9 | 33.3 | 37.7 | 35.0

NOTE: NHIS is National Health Interview Survey; FHS is Follow-up Health Study.

SOURCE: National Center for Health Statistics, National Health Interview Survey Follow-up Health Study, 2021.

Compounding this problem was the difference in NHIS in-person interview rates between PSUs selected for the pilot study and PSUs not selected for the pilot study. Within the two regional offices with NHIS FHS sample, the Sample Adult in-person rate in PSUs selected for the NHIS FHS sample (35.0%) was lower than the Sample Adult in-person rate in PSUs not selected for the NHIS FHS sample (51.0%) between June and September 2021 (Table 7). The difference was particularly large in June. That month, the Sample Adult in-person rate in PSUs in the NHIS FHS sample was 29.6%, while the Sample Adult in-person rate in the non-NHIS FHS PSUs was 51.9%. The difference decreased over the next 3 months of the introduction period, which may have contributed to the higher agreement rate in July–September compared with June.

### Inadequate Incentive

Another possible period effect was the insufficient monetary incentive relative to the burden an in-home health examination may have represented to NHIS respondents. FRs in the focus groups reported that the incentive and argument for the value of participation was inadequate to convince reluctant respondents (7). According to the FRs, while some respondents appreciated that the study offered to give back something tangible, unlike NHIS which does not offer an incentive, the dollar amount of the incentive was too low relative to the burden and time of the home examination, particularly for respondents with high incomes and for those with multiple jobs and very limited leisure time with their families. Also, it may not have seemed relevant to respondents who were concerned that a visiting ExamOne health representative would increase their risk of COVID-19 (7). The results report was motivating for a few respondents, but others reported that they already received their health measurements from their annual physical examination (7).

A little more than one-quarter of responding FRs (28.6%) said the incentive was very helpful for convincing reluctant Sample Adults to participate, and an additional 37.1% reported it was somewhat helpful. However, 20.0% reported it was neither helpful nor unhelpful, and 10.0% reported it was unhelpful or very unhelpful. (7). Furthermore, when asked how the incentive could be improved for the future, 46.4% of responding FRs suggested increasing the incentive or adding more benefits.

Also, even with the incentive, 45.8% of responding FRs reported that it was somewhat difficult to convince Sample Adults to participate, and an additional 12.5% reported it was very difficult. Only 1.4% reported it was very easy and only 7.0% reported it was easy.

### FR Concerns About Impact on Sample Child Interview Completion

Some FRs in the focus groups expressed concerns that asking the Sample Adult if they would be willing to be contacted for NHIS FHS would reduce their willingness to complete the Sample Child interview (7). This concern was also reported in the responses to the FR survey. About one-third or 23.6% of responding FRs indicated they were concerned, and 9.7% indicated they were very concerned. There was no evidence that this occurred, however. In households with both an eligible Sample Adult who completed a Sample Adult interview and an eligible Sample Child, the percentage of households who completed the Sample Child interview was higher among households whose Sample Adult was asked about FHS compared with those whose Sample Adult was not asked (91.1% compared with 85.2%). In addition, there was no evidence that the rate of completed Sample Child interviews differed by whether the Sample Adult agreed to be contacted (89.6%) or refused (91.7%). However, this concern may have decreased FRs’ willingness to try to gain Sample Adult agreement to allow their contact information to be shared.