# Introduction

There has long been interest in combining the strengths of the National Center for Health Statistics’s (NCHS) flagship household health data collection systems, the National Health Interview Survey (NHIS) and the National Health and Nutrition Examination Survey (NHANES). The goals of both surveys are to track national health status, healthcare access, and progress toward achieving national health objectives. Both surveys collect survey data through household interviews from nationally representative samples of the U.S. civilian noninstitutionalized population. The NHIS sample size (about 28,000 households a year) is large enough to calculate reliable annual estimates and subnational estimates for detailed geographic and sociodemographic groups. However, it does not include any physical measurements or collection of biospecimens. NHANES, in contrast, collects the nation’s gold standard nationally representative health data using physical examinations and laboratory measurements in a standardized environment, in addition to survey data. However, its sample is currently too small to produce statistically reliable annual estimates, and its ability to make subnational estimates is more limited compared with NHIS.

The NHANES sample size limitation is a direct consequence of the infrastructure, staffing, and cost logistics that enable NHANES to produce its gold standard estimates. Specifically, the physical examination and biospecimen collection is conducted following the home survey interview, in specially designed and equipped mobile examination centers (MECs) that travel the country with a dedicated, full-time staff of health professionals, offering standardized environments for data collection. Although it would not be feasible, or easily affordable, to expand this system so it could collect data from the full dispersed NHIS sample, it would conceivably be possible to send trained health professionals to visit the homes of NHIS respondents and conduct health examinations. The addition of physical measurements and biospecimen analytic results to the NHIS data set could enable the release of annual estimates based on these data for detailed geographic, demographic, and socioeconomic groups. Even though the data would not be as precise as the measured biological data collected by NHANES, it would still enable NCHS to produce more timely estimates of national health status and progress toward achieving national health objectives, like increased health equity between detailed population groups.

In 2012, NHANES and NHIS collaborated on a pilot study designed to assess the possibility of collecting high-quality physical measurements and biospecimens in the homes of survey participants. Specifically, the Health Measures at Home Study compared health measurements of height, weight, blood pressure, and results from assays of blood collected by NHANES staff (health technicians, physicians, and phlebotomists) from the same NHANES participants in the MEC to measurements collected in the participants’ homes. In the home, the blood and measurements were collected twice, once by a field interviewer and once by a health technician hired specifically for the pilot study (1–3). The equipment used in the home differed from that used in the MEC, and the blood collection differed substantially: venous blood in the MEC and dried blood spots in the home. That study found that both the field interviewers and health technicians were able to collect height, weight, and blood pressure from at least 98% of participants and dried blood spots from at least 96% of participants. Additionally, the correlations between all height and weight measurements were higher than 99% (1). The blood pressure measurements were also close, and although measurements obtained by the field interviewer in the home were higher on average than those obtained by the health technician, the magnitude of the differences was less than 5 mmHg, which is within the range of acceptable differences between blood pressure measurements according to standards of the Association for the Advancement of Medical Instrumentation (3). In contrast, while hemoglobin A1c from dried blood spots collected by field interviewers and health technicians in the home were comparable to results from assays of venous blood, the same was not true for measurements of total and high-density lipoprotein (HDL) cholesterol (2).

Although the Health Measures at Home Study demonstrated that physical measures like height, weight, and blood pressure could be measured successfully in the home, it did not evaluate the feasibility of collecting urine or venous blood in the home, although both can provide important health insights. The latter is of particular interest because of the greater accuracy of venous blood assays and the increased number of assays that can be completed with the larger quantity of blood collected through venous methods compared with dried blood spots. Also, the Health Measures at Home Study, which used a convenience sample of NHANES participants who had already completed their MEC examination when invited to participate in the Health Measures at Home Study, could not evaluate respondents’ willingness to participate in, or the specific challenges of adding, a physical examination to a survey like NHIS that does not currently ask anything extra from respondents. Although up to three adult respondents are allowed per NHIS household, the NHIS respondent of interest for this purpose is the Sample Adult. The Sample Adult is the adult household resident who is randomly selected by the NHIS instrument to answer detailed health questions about themselves. More information on NHIS respondents is provided in “Methods.”

In 2019, NHIS asked about Sample Adults’ willingness to participate in a hypothetical study in which a nurse would come to their home and measure their height, weight, and blood pressure, collect a blood sample, and provide an unspecified incentive. About 35% of NHIS Sample Adults were somewhat or very willing to participate in such a hypothetical in-home examination (4). However, this information was collected before the COVID-19 pandemic, and it was unknown how the pandemic might impact respondents' willingness to agree to in-home measurements.

In 2021, NHIS and NHANES collaborated on the 2021 NHIS Follow-up Health Study (FHS) to learn more about the feasibility of adding an in-home health examination, including physical measures, venous blood, and urine collection, to NHIS.

## Goals and Research Questions

NHIS FHS had two goals. The first was to learn if NHIS Sample Adults who completed the Sample Adult interview would be willing to participate in an in-home physical examination conducted by a health professional in the weeks following their NHIS interviews, consisting of measurement of height, weight, waist circumference, and blood pressure, and collection of a blood and urine sample. The second was to determine the feasibility of, and potential challenges to, implementing such pilot examination procedures among NHIS’s large-scale, geographically dispersed national sample. This study had the following research questions:

- What percentage of NHIS adult respondents who have completed their Sample Adult interview will participate in each stage of the in-home health examination process?
  - What percentage introduced to the study will give permission for their contact information to be given to a private, nonfederal company scheduling the appointments and conducting the examinations on behalf of NCHS?
  - What percentage who give permission to share their contact information will schedule an appointment?
  - What percentage who schedule appointments will start the in-home examination?
  - What percentage who start the in-home examination will complete each examination component?
  - What percentage of the blood and urine specimens provided by Sample Adults will be of sufficient quantity for analysis?
  - What concerns will Sample Adults have at each stage, what reasons will they give for refusing, and what reasons will examination participants give for participating?
- What are the operational challenges of each step of the in-home health examination process?
  - Gaining initial agreement to participate
  - Scheduling the home health visit appointments
  - Conducting the in-home examinations
  - Packaging, shipping, and analyzing the biospecimens from, and reporting the results of, these home health examinations

## Report Organization

This report is organized into seven main sections. The first section provides an overview of the study methods, including the constraints that determined many of the operational parameters. The second through sixth sections provide results answering the research questions. The final section discusses the feasibility of implementing these procedures among the full NHIS sample. This section includes a summary of the challenges encountered in the pilot study that would be minimized or eliminated if the procedures were implemented with the full sample.