# References

1 Gindi R, Zipf G, Galinsky A, Miller I, Nwankwo T, Terry A. Comparison of in-home collection of physical measurements and biospecimens with collection in a standardized setting: the Health Measures at Home Study. National Center for Health Statistics. Vital Health Stat 2(164). 2014.
2 Miller IM, Lacher DA, Chen TC, Zipf GW, Gindi RM, Galinsky AM, et al. Collection and laboratory methods for dried blood spots for hemoglobin A1c and total and high-density lipoprotein cholesterol in population-based surveys. Clin Chim Acta 445:143–54. 2015. 10.1016/j.cca.2015.03.028.25818242
3 Nwankwo T, Gindi G, Chen T, Galinsky A, Miller I, Terry A. Comparison of blood pressure measurements obtained in the home setting: Analysis of the Health Measures at Home Study. Blood Pres Monit 21(6):327–34. 2016.
4 Zablotsky B, Galinsky AM, Maitland A, Medley GE, Villarroel MA, Warren AJ. When expectation meets reality: A comparison of respondent willingness to participate in a hypothetical versus pilot follow-up study to the National Health Interview Survey. American Association for Public Opinion Research Annual Meeting. Chicago, IL. May 11, 2022.
5 Galinsky AM, Simile C, Zelaya CE, Norris T, Panapasa SV. Surveying strategies for hard-to-survey populations: Lessons from the Native Hawaiian and Pacific Islander National Health Interview Survey. Am J Public Health 109(10):1384–91. 2019. DOI: 10.2105/AJPH.2019.305217.31415207
6 National Center for Health Statistics. National Health Interview Survey, 2019 survey description. 2020. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/NHIS/2019/srvydesc-508.pdf.
7 Terry RL, Genter S, Class BO, O ’Brian A, Luck J. Mixed method research of field representative feedback on the NHIS Biomeasures Study. Center for Behavioral Science Methods, Research and Methodology Directorate, U.S. Census Bureau. 2022.
8 Shanahan L, Steinhoff A, Bechtiger L, Murray AL, Nivette A, Hepp U, et al. Emotional distress in young adults during the COVID-19 pandemic: Evidence of risk and resilience from a longitudinal cohort study. Psychol Med 52(5):824–33. 2022.32571438
9 National Center for Health Statistics. National Health Interview Survey, 2021 survey description. 2022. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Dataset_Documentation/NHIS/2021/srvydesc-508.pdf.
10 Lee CM, Cadigan JM, Rhew IC. Increases in loneliness among young adults during the COVID-19 pandemic and association with increases in mental health problems. J Adolesc Health 67(5):714–7. 2020.33099414
11 Thaler RH, Sunstein CR. Nudge: Improving decisions about health, wealth, and happiness. New York, NY: Penguin Books. 2009.
12 National Center for Health Statstics. National Health and Nutrition Examination Survey (NHANES): Interviewer procedures manual. 2020. Available from: https://wwwn.cdc.gov/nchs/data/nhanes/2019-2020/manuals/2020-Interviewer-Procedures-Manual-508.pdf.
13 U.S. Census Bureau. National Health Interview Survey: 2024 CAPI manual for NHIS field representatives. 2023. Available from: https://ftp.cdc.gov/pub/Health_Statistics/NCHS/Survey_Questionnaires/NHIS/2024/frmanual-508.pdf.