# Appendix IX. Appointment Reminder

[underlined: Voicemail script for health representative:]

Hello, this is (NAME) from ExamOne. I’m calling to confirm your home health visit with me on (MONTH, DAY) at (TIME). Please call (PROVIDE YOUR PROJECT CELL PHONE NUMBER) for important reminders about the visit.

Thanks and see you soon.

[underlined: Phone script for health representative:]

Hello, my name is , may I please speak with (PARTICIPANT NAME)? _______

Participant not home or unavailable:

Can you please ask {him/her} to call me at <health representative’s contractor‐provided cell phone number>?

When is the best time to reach (PARTICIPANT NAME)?

Participant is available but person on the phone wants to know who is calling before handing the phone over:

I’m calling on behalf of the CDC’s National Center for Health Statistics.

Participant is on the line now but wasn’t the person who answered the phone :

Hello, my name is. [Continue with Speaking to the participant.] ____________

Speaking to the participant:

I’m calling from the National Health Interview Survey Follow‐up Health Study. I’m calling to confirm your home health visit with me on (MONTH, DAY) at (TIME).

Before I come to your home, I need to ask you again about COVID‐19 symptoms you may have or possible exposure to someone with COVID‐19

[Read COVID screening questions.]

[If participant responds “YES” to any COVID screening question, reschedule the participant’s home health visit for a date more than 14 days after the current date, if the study will still be active at that time.]

Before the visit, please be sure to drink plenty of water, wear short sleeves, and have a photo ID ready. We also recommend that you wear a mask. Some of your tests will be more accurate if you do not eat for 8 hours before the appointment. But you can still take part in the study no matter when you last ate. Do you have any questions?

[Answer any questions the respondent has.]

If any of your answers to the COVID‐19 questions change before my visit, please call me. My phone number is (PROVIDE YOUR PROJECT CELL PHONE NUMBER). Thank you.