# Appendix VIII. Noncontact and Refusal Letters

Two letters. First letter thanks respondents for agreeing to participate in the National Health Interview Survey Follow-up Health Study and providing information to schedule an appointment. Second letter encourages respondents who previously refused to participate in the study to participate.